# REFERENCES

1 Powell A, Rushmer R, Davies H. A systematic review of quality improvement models in health care. NHS Quality Improvement Scotland. 2008.
2 Rubenstein L, Khodyakov D, Hempel S, . How can we recognize continuous quality improvement? Int J Qual Health Care. 2014;26(1):6–15.24311732
3 Hill JE, Stephani AM, Sapple P, Clegg AJ. The effectiveness of continuous quality improvement for developing professional practice and improving health care outcomes: a systematic review. Implement Sci. 2020;15(1):23.32306984
4 Shea BJ, Reeves BC, Wells G, . AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. 2017;358:j4008.28935701
5 Rubenstein LV, Hempel, S., Liu, J.L., Danz, M.J., Foy, R., Lim, Y.W., Motala, A. and Shekelle, P.G. The Minimum Quality Criteria Set (QI-MQCS) for critical appraisal: advancing the science of quality improvement. Implementation Science: IS. 2015;10:A19.
6 King N. Template analysis. 1998.
7 Damschroder LJ, Aron, D.C., Keith, R.E. . Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implementation Science. 2009;4(50).
8 Aij KH, Teunissen M. Lean leadership attributes: a systematic review of the literature. J Health Organ Manag. 2017;31(7-8):713–729.29187082
9 Amaratunga T, Dobranowski J. Systematic Review of the Application of Lean and Six Sigma Quality Improvement Methodologies in Radiology. J Am Coll Radiol. 2016;13(9):1088–1095.e1087.27209599
10 Bucci S, de Belvis AG, Marventano S, . Emergency Department crowding and hospital bed shortage: is Lean a smart answer? A systematic review. Eur Rev Med Pharmacol Sci. 2016;20(20):4209–4219.27831655
11 Côté A, Beogo I, Abasse KS, Laberge M, Dogba MJ, Dallaire C. The clinical microsystems approach: Does it really work? A systematic review of organizational theories of health care practices. J Am Pharm Assoc (2003). 2020;60(6):e388–e410.32698951
12 DelliFraine JL, Langabeer JR, II, Nembhard IM. Assessing the evidence of Six Sigma and Lean in the health care industry. Qual Manag Health Care. 2010;19(3):211–225.20588140
13 DelliFraine JL, Zheng W, McCaughey D, Langabeer Ii JR, Erwin C. The Use of Six Sigma in Health Care Management: Are We Using It to Its Full Potential? Qual Manag Health Care. 2013;22(3):210–223.23807133
14 Dzidowska M, Lee KSK, Wylie C, . A systematic review of approaches to improve practice, detection and treatment of unhealthy alcohol use in primary health care: a role for continuous quality improvement. BMC Fam Pract. 2020;21(1):33.32054450
15 Glasgow JM, Scott-Caziewell JR, Kaboli PJ. Guiding inpatient quality improvement: a systematic review of Lean and Six Sigma. Jt Comm J Qual Patient Saf. 2010;36(12):533–540.21222355
16 Hill JE, Stephani A-M, Sapple P, Clegg AJ. The effectiveness of continuous quality improvement for developing professional practice and improving health care outcomes: a systematic review. Implement Sci. 2020;15(1):23.32306984
17 Hulscher MEJL, Schouten LMT, Grol RPTM, Buchan H. Determinants of success of quality improvement collaboratives: what does the literature show? BMJ Qual Saf. 2013;22(1):19–31.
18 Mousavi Isfahani H, Tourani S, Seyedin H. Features and Results of Conducted Studies Using a Lean Management Approach in Emergency Department in Hospital: A Systematic Review. Bull Emerg Trauma. 2019;7(1):9–20.30719461
19 Leggat SG, Bartram T, Stanton P, Bamber GJ, Sohal AS. Have process redesign methods, such as Lean, been successful in changing care delivery in hospitals? A systematic review. Public Money & Management. 2015;35(2):161–168.
20 Pestana Magalhães AL, Erdmann AL, Lima da Silva E, Guedes dos Santos JL. Lean thinking in health and nursing: an integrative literature review. Revista Latino-Americana de Enfermagem (RLAE). 2016;24:1–13.
21 Mason SE, Nicolay CR, Darzi A. The use of Lean and Six Sigma methodologies in surgery: a systematic review. Surgeon. 2015;13(2):91–100.25189692
22 Moraros J, Lemstra M, Nwankwo C. Lean interventions in healthcare: do they actually work? A systematic literature review. Int J Qual Health Care. 2016;28(2):150–165.26811118
23 Nadeem E, Olin SS, Hill LC, Hoagwood KE, Horwitz SM. Understanding the components of quality improvement collaboratives: a systematic literature review. Milbank Q. 2013;91(2):354–394.23758514
24 Nicolay CR, Purkayastha S, Greenhalgh A, . Systematic review of the application of quality improvement methodologies from the manufacturing industry to surgical healthcare. Br J Surg. 2012;99(3):324–335.22101509
25 Nunes JW, Seagull FJ, Rao P, Segal JH, Mani NS, Heung M. Continuous quality improvement in nephrology: a systematic review. BMC Nephrol. 2016;17(1):190.27881093
26 Schouten LM, Hulscher ME, van Everdingen JJ, Huijsman R, Grol RP. Evidence for the impact of quality improvement collaboratives: systematic review. BMJ. 2008;336(7659):1491–1494.18577559
27 Talib F, Rahman Z, Azam M. Best practices of total quality management implementation in health care settings. Health Mark Q. 2011;28(3):232–252.21815741
28 Taylor MJ, McNicholas C, Nicolay C, Darzi A, Bell D, Reed JE. Systematic review of the application of the plan-do-study-act method to improve quality in healthcare. BMJ Qual Saf. 2014;23(4):290–298.
29 Tlapa D, Zepeda-Lugo CA, Tortorella GL, . Effects of Lean Healthcare on Patient Flow: A Systematic Review. Value Health. 2020;23(2):260–273.32113632
30 Trakulsunti Y, Antony J, Ghadge A, Gupta S. Reducing medication errors using LSS methodology: A systematic literature review and key findings. Total Quality Management and Business Excellence. 2018:1–19.
31 Tricco AC, Ivers NM, Grimshaw JM, . Effectiveness of quality improvement strategies on the management of diabetes: a systematic review and meta-analysis. Lancet. 2012;379(9833):2252–2261.22683130
32 Wackerbarth SB, Bishop SS, Aroh AC. Lean in Healthcare: Time for Evolution or Revolution? Journal for Healthcare Quality: Promoting Excellence in Healthcare. 2021;43(1):32–38.
33 Woodnutt S. Is Lean sustainable in today’s NHS hospitals? A systematic literature review using the meta-narrative and integrative methods. Int J Qual Health Care. 2018;30(8):578–586.29648651
34 Zamboni K, Baker U, Tyagi M, Schellenberg J, Hill Z, Hanson C. How and under what circumstances do quality improvement collaboratives lead to better outcomes? A systematic review. Implement Sci. 2020;15(1):27.32366269
35 Zepeda-Lugo C, Tlapa D, Baez-Lopez Y, . Assessing the Impact of Lean Healthcare on Inpatient Care: A Systematic Review. Int J Environ Res Public Health. 2020;17(15).
36 Crema M, Verbano C. Lean Management to support Choosing Wisely in healthcare: the first evidence from a systematic literature review. Int J Qual Health Care. 2017;29(7):889–895.29045684
37 Maijala R, Eloranta S, Reunanen T, Ikonen TS. SUCCESSFUL IMPLEMENTATION OF LEAN AS A MANAGERIAL PRINCIPLE IN HEALTH CARE: A CONCEPTUAL ANALYSIS FROM SYSTEMATIC LITERATURE REVIEW. Int J Technol Assess Health Care. 2018;34(2):134–146.29642955
38 Mazzocato P, Savage C, Brommels M, Aronsson H, Thor J. Lean thinking in healthcare: a realist review of the literature. Qual Saf Health Care. 2010;19(5):376–382.20724397
39 D’Andreamatteo A, Ianni L, Lega F, Sargiacomo M. Lean in healthcare: A comprehensive review. Health Policy. 2015;119(9):1197–1209.25737260
40 Antony J, Palsuk P, Gupta S, Mishra D, Barach P. Six Sigma in healthcare: a systematic review of the literature. International Journal of Quality & Reliability Management. 2018.
41 Niñerola A, Sánchez-Rebull M-V, Hernández-Lara A-B. Quality improvement in healthcare: Six Sigma systematic review. Health Policy. 2020;124(4):438–445.32156468
42 Andersen H, Røvik KA, Ingebrigtsen T. Lean thinking in hospitals: is there a cure for the absence of evidence? A systematic review of reviews. BMJ Open. 2014;4(1):e003873.
43 Ogrinc G, Davies L, Goodman D, Batalden P, Davidoff F, Stevens D. SQUIRE 2.0 (Standards for QUality Improvement Reporting Excellence): revised publication guidelines from a detailed consensus process. BMJ Qual Saf. 2016;25(12):986–992.