# ACKNOWLEDGMENTS

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Vince Watts, MD
  Interim Director
  VA Office of System Redesign and Improvement (10E2F)

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- David Ganz, MD, PhD
  Associate Director, VA HSR&D Center for the Study of Healthcare Innovation, Implementation & Policy, VA Greater Los Angeles Healthcare System
  Professor of Medicine, UCLA School of Medicine
- Laura Damschroder, MPH, MS
  Research Investigator, VA Ann Arbor Center for Clinical Management Research
  Project Principal Investigator, Personalizing Options through Veteran Engagement Quality Enhancement Research Initiative (QUERI)
- Kyler Godwin, PhD, MPH
  Director, Coordinating Center, National VA Quality Scholars Program
  Assistant Professor, Department of Medicine, Baylor College of Medicine
- Elizabeth Yano, PhD, MSPH
  Director and Senior Research Career Scientist, VA HSR&D Center for the Study of Healthcare
  Innovation & Policy, VA Greater Los Angeles Healthcare System
  Adjunct Professor of Health Policy & Management, University of California Los Angeles Fielding School of Public Health

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.