# SUMMARY AND DISCUSSION

We sought to identify effective CQI interventions (Key Question 1) and conditions necessary for their success (Key Question 2) in a review of reviews.

Our systematic review of reviews is innovative in that it used a rigorous search and review methodology to include a breadth of systematic reviews on each of these Key Questions. Additionally, we evaluated the certainty of evidence for each Key Question using a modification of the AMSTAR2 tool for systematic reviews. No included reviews specifically addressed care of Veterans as a study objective nor were any conducted fully in VA settings, although several individual articles within the included systematic reviews were based at VA.

## SUMMARY OF EVIDENCE BY KEY QUESTION

Key Question 1A What is the comparative effectiveness of implementing continuous quality improvement frameworks in terms of health care workers’ reaction, learning, behavior change, results, and sustainment of change?

We assessed the literature for evidence regarding the comparative effectiveness of different CQI strategies. However, we were only able to identify a single study^1^ with an AMSTAR2 rating of 2 that met inclusion criteria. This study is over a decade old and found no evidence that any single CQI strategy was more effective than others. Instead, the authors concluded that local context should guide which framework is ultimately implemented.

Key Question 1B What is the effectiveness of implementing a continuous quality improvement framework in terms of health care workers’ reaction, learning, behavior change, results, and sustainment of change?

Having found only a single study comparing the effectiveness of different CQI strategies, we then turned to assess the 25 reviews that studied at least 1 framework for evidence of effectiveness for a variety of outcomes. None of the 11 reviews that examined more than 1 CQI methodology reached a conclusion that any strategy was superior to the others in terms of results. However, many frameworks have been successfully implemented in a variety of clinical settings. In some clinical settings, such as in the OR and ED, multiple different strategies have been used in different geographic locations. Several studies had AMSTAR2 ratings of at least 8; however, studies with higher AMSTAR2 scores did not draw more specific conclusions than studies with lower scores.

Similarly, none of the 7 reviews discussing sustainment of change identified a superior strategy. Additionally, no study directly commented on health care workers’ reactions in being involved as part of CQI framework implementation, what health care workers learned or retained as part of CQI training, nor behavior changes noted after implementation of a CQI strategy.

Key Question 2 What factors (including intervention, inner setting, outer setting, individuals involved, and process by which implementation is accomplished) contribute to the success or failure of these continuous quality improvement frameworks?

We then assessed the literature for evidence regarding success or failure factors associated with CFIR factors. Ultimately, 20 reviews studied at least 1 CFIR factor; however, none compared the success or failure of different CQI strategies based on intervention characteristics, characteristics of individuals, or inner setting. Instead, the majority of studies listed aspects of some or each of these 3 CFIR categories deemed important for implementation of that CQI methodology with little to no supporting evidence. No study included in this review discussed whether either outer setting or specific processes during implementation of a CQI framework contributed to either the success or failure of implementation for any framework.

## LIMITATIONS

Our review has a number of strengths, including a protocol-driven design, a comprehensive search, and careful quality assessment. Both our review and the literature, however, have limitations. Our review was limited to English-language publications, but the likelihood of identifying relevant data unavailable from English-language sources is low. Identified studies, with 1 exception, did not discuss comparative effectiveness, and none compared different methodologies for the other outcomes of interest. The single study explicitly discussing comparative effectiveness was identified via reference mining given its age. We chose to include this article, despite not making our publication date cut-off, as it was the only study we identified directly address the first Key Question. Similarly, one limitation of the review of reviews approach is an inability to closely align the inclusion criteria or scopes of the individual systematic reviews. Other limitations are detailed below.

### Publication Bias

Multiple included systematic reviews noted the possibility of publication bias across the quality improvement methodologies, with positive results greatly outnumbering null or negative findings. Given our focus on systematic reviews for this study, quantitative publication bias analysis was not appropriate.

### Quality of Included Reviews

We were also limited by the existing literature. We utilized a modified version of the AMSTAR2 tool for articles deemed appropriate for its use, finding 9 of 29 studies for which we were able to use the tool had a score of at least 8. These nine studies did not differ substantially in their conclusions from other articles included with lower AMSTAR2 scores. These low ratings on the AMSTAR2 tool leads us to conclude the overall certainty of evidence related to these reviews is low to moderate.

Reasons for the low AMSTAR2 scores of identified studies may include underlying issues with study design and implementation in the primary QI literature, as well as with study reporting. Most QI initiatives are designed and implemented in pragmatic clinical or operational settings, which may limit overall study quality for inclusion into a systematic review. Even when sufficient elements are included in QI projects, however, the elements may not be fully explained in subsequent manuscripts. Such issues may then be compounded in performing and reporting systematic reviews. In general, fewer than 40% of our included systematic reviews reported the following: specific comparators as an inclusion criteria (19%); PROSPERO registration (15%); explanation for inclusion of non-randomized controlled trial methodologies within the review (37%); duplicate data extraction (37%); justifications in a list or figure for exclusion of studies (37%); results of comparators found in individual trials (4%); review for risk of bias of included studies (26%); and discussion of heterogeneity found (26%).

### Applicability of Findings to the VA Population

Several studies included work done within VA as part of their larger reviews. Additionally, most reviews focused on studies performed in Organisation for Economic Co-operation and Development countries, which generally have well-funded health care systems and which improves applicability to VA. The only review mentioning comparative effectiveness was conducted in the United Kingdom and included reflections on the VA QUERI program. Across included reviews, there were limited data on intervention and setting characteristics to compare to the overall VA population. However, the findings presented here likely have applicability to any large health care system seeking to implement a multi-site improvement methodology.

Within VA, there are several ongoing initiatives that use CQI methodologies or frameworks with CQI elements, such as the Evidence-Based Quality Improvement (EBQI) Training Hub and The Learn. Engage. Act. Process. (LEAP) Program, in addition to the focus on Lean in systems redesign. These current efforts may not be represented universally in the published literature, nor were any of these initiatives specifically identified in the systematic reviews that comprised this review of reviews, limiting our ability to discuss comparisons with other strategies. However, these initiatives may provide opportunities for future comparative evaluations of CQI methods.

## RESEARCH GAPS/FUTURE RESEARCH

This comprehensive review of the literature identified several gaps in the current evidence that warrant future investigation, even across studies with higher AMSTAR2 ratings. The most notable of these gaps is a lack of comparative studies analyzing multiple CQI methodologies within health care settings. Although such comparative examples may be identifiable in other fields, such as manufacturing, the complexity of healthcare processes, the differences in outcomes pertaining to health, and the variability in local contexts for implementation of QI methodologies within health care warrants creation of such studies. As noted above, current VA efforts from resources such as the EBQI or LEAP programs may provide opportunities to promote such comparative investigations. An alternative approach would be to attempt meta-analysis of multiple CQI methodologies with narrow questions in specific settings from the existing primary literature, such as waiting times in emergency departments. However, given the limitations of the systematic reviews in our review of reviews, such an initiative would likely require sharing and re-analysis of the primary data from the original studies.

The overall evidence base would be improved if future reported individual QI studies more closely adhered to SQUIRE 2.0 reporting standards.^5,43^ Similarly, future systematic reviews of these works would be stronger by considering the AMSTAR2 categories we found to be often lacking, such as specifying comparators as an inclusion criteria and sharing the results of comparators from individual trials, PROSPERO registration, and explicitly discussing risk of bias.

## CONCLUSIONS

Prior systematic reviews of CQI strategies have, with 1 exception, not compared the effectiveness of different methodologies. Instead, many published reviews have shown success for 1 or more methodologies within specific contexts. However, these findings are likely subject to significant publication bias from the constituent studies, making the overall certainty of evidence low. Additionally, few data are available regarding sustainment of changes made through CQI and no systematic reviews we identified discussed health care workers’ reactions, learning, or behavior changes related to participating in CQI. Similarly, no systematic reviews compared the success or failure of different CQI frameworks based on intervention characteristics, characteristics of individuals, or inner setting. Furthermore, no studies discussed whether either the outer setting or specific processes during implementation of a CQI framework contributed to either the success or failure of implementation of any methodology. Few systematic reviews included in this review of reviews had high ratings on a modified AMSTAR2 tool, leading us to conclude the overall certainty of evidence related to these topics is low to moderate. Thus, evidence gaps remain regarding whether any CQI strategy is superior to others or how any such methodology should be implemented at large scale within the VA context. Future work should emphasize comparative designs for CQI methodologies. Available resources at VA may help facilitate such work in the future.