# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Vince Watts, MD, Interim Director of VA Office of System Redesign and Improvement (10E2F). Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP):

Key Question 1A What is the comparative effectiveness of implementing continuous quality improvement frameworks in terms of health care workers’ reaction, learning, behavior change, results, and sustainment of change?
Key Question 1B What is the effectiveness of implementing a continuous quality improvement framework in terms of health care workers’ reaction, learning, behavior change, results, and sustainment of change?
Key Question 2 What factors (including intervention characteristics, inner setting, outer setting, individuals involved, and process by which implementation is accomplished) contribute to the success or failure of these continuous quality improvement frameworks?

To be eligible for Key Question 1A, a systematic review had to explicitly focus on comparative effectiveness of multiple CQI methodologies as a stated aim. If a review commented on multiple methodologies but did not seek to compare the effectiveness of the strategies within its methods, it was included in Key Question 1B.

The review was registered in PROSPERO: CRD42021245263.

## SEARCH STRATEGY

Our team, which included a medical librarian, developed and conducted broad systematic review searches using terms relating to “quality improvement” or “continuous quality improvement” or “system redesign” in 4 databases: PubMed, CINAHL, DARE, and Cochrane. Search dates for PubMed are from 01/01/2010 through 03/18/2021. Search dates for CINAHL and Cochrane are from 01/01/2010 through 03/30/2021. Search dates for DARE are from 01/01/2010 to 03/31/2015. We restricted our searches to English language publications. See Appendix A for full search strategy.

## STUDY SELECTION

As multiple reviews on individual or subsets of CQI methodologies have been performed previously, this study was designed as a review of these pre-existing reviews. Three team members working independently screened all titles for relevance; any article chosen by any reviewer was included in the abstract screen. Abstracts were then reviewed in duplicate with any discrepancies resolved by group discussion. Full-text review was conducted independently by team members working in pairs, with any disagreements resolved through discussion. In order to be included, a review had to be a systematic review and include CQI as an intervention within any health care setting. An intervention was deemed to be CQI if it was either explicitly referred to as CQI or comprised of 3 essential features of CQI methods: “systematic data guided activities”, “designing with local conditions in mind”, and “iterative development and testing.”^2^ These strategies included Lean, Six Sigma, Lean Six Sigma, Quality Improvement Collaboratives, CQI (hereafter referred to as the ‘CQI method’ to distinguish from general CQI), Total Quality Management (TQM), Clinical Microsystems, and the Plan-Do-Check-Act (PDCA) or Plan-Do-Study-Act (PDSA) method. Thus, we rejected narrative reviews, scoping reviews, and publications that only reported components of quality improvement (QI) without a full QI framework. Specific definitions for each strategy were not included in our search strategy; rather, we allowed each systematic review to apply its own definitions and labels to the included studies. See Appendix B for the full-text review form.

## DATA ABSTRACTION

Each included systematic review had data abstracted by 2 reviewers independently. Abstracted data included: CQI framework/strategy discussed, whether article described context/factors contributing to the success or failure of the framework/strategy, total number of studies included, search dates, health care condition, health care setting, and geographical region. Any discrepancies in data abstraction were resolved by group discussion.

We used the Consolidated Framework for Implementation Research (CFIR) to guide abstraction and synthesis of Key Question 2 around the following domains: intervention characteristics, inner setting, outer setting, individuals involved, and process by which implementation is accomplished. All studies discussed in Key Question 2 were assessed for inclusion in duplicate, with discrepancies resolved with group discussion.

## QUALITY ASSESSMENT

Each systematic review was assessed using a modified version of the Assessing the Methodological Quality of Systematic Reviews 2 (AMSTAR2) criteria.^4^ This 16-item tool was designed to assess the methodological quality of systematic reviews and meta-analysis and is considered the standard for this type of assessment. The tool includes domains such as descriptions of PICO (population, intervention, comparators, and outcomes) in both inclusion criteria and results, PROSPERO registration, use of a comprehensive and timely literature search strategy, duplicate data abstraction, and analysis of risk of bias. As some AMSTAR2 items concern meta-analysis not applicable to our set of studies, we adapted the tool for this review, resulting in a 13-item tool. The criteria in our modified tool are shown in the table below (Table 1), while the full modified tool is available in Appendix C. One item — “If they performed quantitative synthesis did the review authors carry out an adequate investigation of publication bias (small study bias) and discuss its likely impact on the results of the review?” — was found not to be applicable in all included reviews and therefore is excluded from Tables 1 and 2.

Assessment of studies using our modified tool was completed in duplicate, with discrepancies resolved with group discussion. No study was excluded from analysis based on AMSTAR2 score; however, we chose a score of greater than or equal to 8 to represent higher-quality systematic reviews. Reviews with a score of 7 or lower had the potential for multiple methodological flaws (given that they either did not do or did not report doing some key methodological practices), which influenced our interpretation of the completeness and rigor of their findings and conclusions. This cut-off was used in formulating certainty of evidence statements, as described below.

Table 1 Modified AMSTAR2 Questions

1. | Did the research questions and inclusion criteria for the review include a) population/setting; b) intervention; c) comparator(s); d) outcomes?
2. | Did the report of the review reference a protocol or PROSPERO registration?
3. | Did the review authors explain their selection of other study designs (non-RCTs) for inclusion in the review?
4. | Did the review authors use a comprehensive literature search strategy?
5. | Did the review authors perform study selection in duplicate?
6. | Did the review authors perform data extraction in duplicate?
7. | Did the review authors provide a list of excluded studies and/or justify the exclusions?
8. | Did the review authors describe the following components in individual included studies in adequate detail: a) populations/settings; b) interventions; c) comparators(s); d) outcomes; e) research designs?
9. | Did the review authors use a satisfactory technique for assessing the risk of bias (RoB) in individual studies that were included in the review?
10. | Did the review authors account for RoB in individual studies when interpreting/discussing the results of the review?
11. | Did the review authors provide a satisfactory explanation for, and discussion of, any heterogeneity observed in the results of the review?
12. | Did the review authors report any potential sources of conflict of interest, including any funding they received for conducting the review?

Reviews reporting results relevant to our key questions that used an established method of synthesis other than traditional systematic review methods, such as comprehensive reviews and realist reviews, were not assessed with AMSTAR2, given that AMSTAR2 was developed for systematic review and meta-analysis methods.

While quality criteria specifically for quality improvement studies have been developed, like the Quality Improvement Minimum Quality Criteria Set,^5^ they are designed for primary research articles, and as such are not appropriate for use with the systematic reviews this report discusses. Nonetheless, we did take into account the Quality Improvement Minimum Quality Criteria Set and our discussion of Key Question 2 is informed by these criteria.

## DATA SYNTHESIS AND ANALYSIS

Our review is a narrative analysis. For KQ1A and KQ1B we narratively synthesized the evidence from relevant included systematic reviews based on CQI frameworks and outcomes reported. For KQ2, we conducted a template analysis using the included systematic reviews as our source material.^6^ We looked at factors affecting the success or failure of CQI frameworks according to the 5 main Consolidated Framework for Implementation Research (CFIR) domains.^7^ We used the CFIR domains as the basis for our coding structure, capturing any relevant language in the included systematic reviews that described 1) intervention characteristics, 2) inner setting, 3) outer setting, 4) individuals involved, and/or 5) process by which implementation is accomplished.^7^

Certainty of evidence was determined by use of overall AMSTAR2 scores. We categorized evidence into low, moderate, and high certainty by the frequency with which included reviews for each key question had an AMSTAR2 score greater than or equal to 8. Key questions with fewer than 1/3 of studies having a score ≥ 8 were categorized as low certainty of evidence, those with between 1/3 and 2/3 of studies with scores ≥ 8 as moderate certainty of evidence, and those with > 2/3 of studies with scores ≥ 8 as high certainty of evidence.

## PEER REVIEW

A draft version of the report was reviewed by technical experts and clinical leadership. While Technical Panel Experts are often asked to also serve as peer reviewers, we also invite experts who have not been involved with the current project to serve as peer reviewers. Reviewer comments and our responses are documented in Appendix D.