# INTRODUCTION

As part of its mandate to optimize health outcomes for Veterans, the Department of Veterans Affairs (VA) has an incentive to improve the quality and safety of health care. Standardizing a process improvement methodology and training across the entire VA has the potential to expand resources for local improvement activities, particularly in settings such as individual clinics or units that may have fewer currently trained personnel to support project leadership and management, and improve the quality and efficiency of care delivery.

Continuous quality improvement (CQI) frameworks are system-level approaches to improving the quality and safety of health care through systematic data-guided activities, iterative development and testing of processes, and designing with local conditions in mind.^2,3^ Lean Management (Lean) – a process adapted from a 1930s manufacturing model by the Toyota Corporation that seeks to increase efficiencies and reduce waste – has subsequently been applied to a variety of medical and industrial settings and is one of the most popular CQI frameworks in health care settings. In December 2019, the Deputy Under Secretary for Health issued a directive outlining the deployment of a new VA-wide program for systems redesign and improvement.^3^ As part of this directive, Lean was designated as the primary process improvement methodology to be utilized across the VA.

Despite designation as the preferred CQI methodology, there is uncertainty as to whether Lean is superior to other CQI frameworks, such as the Institute for Healthcare Improvement (IHI)’s Model for Change or Clinical Microsystems. There is also uncertainty as to whether certain intervention-level or health system-level factors affect the success or failure of specific CQI methodologies, such as rigorous training of staff or health system academic affiliation.

Several reviews on CQI methodologies exist; however, none identified in a preliminary literature search by the Evidence Synthesis Program (ESP) Coordinating Center currently cover all interventions, settings, and outcomes of interest. Therefore, this current review of reviews was requested by the VA Office of Systems Redesign and Improvement (SRI), which is charged with partnering with Veterans Integrated Service Networks (VISNs) in implementing the 2019 directive. This report will be used to identify effective CQI frameworks and conditions necessary for their success for dissemination and training across the VA by the SRI.