# APPENDIX F CITATIONS FOR EXCLUDED PUBLICATIONS

## Does Not Discuss Key Questions, n=69

1 Agarwal, A., ., Hospital-based quality improvement interventions for patients with heart failure: a systematic review. Heart (British Cardiac Society), 2019. 105(6): p. 431–438.30700515
2 Alagoz, E., ., The use of external change agents to promote quality improvement and organizational change in healthcare organizations: a systematic review. BMC health services research, 2018. 18(1): p. 42.29370791
3 Antierens, A., ., How much of Toyota’s philosophy is embedded in health care at the organisational level? A review. Journal of Nursing Management (John Wiley & Sons, Inc.), 2018. 26(4): p. 348–357.
4 Atassi, K., Strategies to increase colorectal cancer screening. Nurse Practitioner, 2012. 37(7): p. 21–26.
5 Bahiru, E., ., Hospital-Based Quality Improvement Interventions for Patients With Acute Coronary Syndrome: A Systematic Review. Circulation. Cardiovascular quality and outcomes, 2019. 12(9): p. e005513.31525081
6 Bakker, F.C., S.H.M. Robben, and M.G.M. Olde Rikkert, Effects of hospital-wide interventions to improve care for frail older inpatients: a systematic review. BMJ quality & safety, 2011. 20(8): p. 680–691.
7 Bastemeijer, C.M., ., Patient experiences: a systematic review of quality improvement interventions in a hospital setting. Patient related outcome measures, 2019. 10: p. 157–169.31191062
8 Bergerum, C., ., How might patient involvement in healthcare quality improvement efforts work—A realist literature review. Health Expectations, 2019. 22(5): p. 952–964.31044517
9 Beyranvand, T., A. Aryankhesa, and A.A. Hashjin, Quality improvement in hospitals’ surgery-related processes: A systematic review. Journal of Medical Council of Islamic Republic of Iran, 2019. 33(1): p. 1–9.
10 Chakraborty, A., ., The effectiveness of in-hospital interventions on reducing hospital length of stay and readmission of patients with Type 2 Diabetes Mellitus: a systematic review. Diabetes research and clinical practice, 2020: p. 108363.
11 Chaudhuri, D., ., Effectiveness of Quality Improvement Interventions at Reducing Inappropriate Cardiac Imaging: A Systematic Review and Meta-Analysis. Circulation. Cardiovascular quality and outcomes, 2016. 9(1): p. 7–13.26733588
12 Clay-Williams, R., ., Do large-scale hospital- and system-wide interventions improve patient outcomes: a systematic review. BMC health services research, 2014. 14: p. 369.25187292
13 Cleveringa, F.G.W., ., Computerized decision support systems in primary care for type 2 diabetes patients only improve patients’ outcomes when combined with feedback on performance and case management: a systematic review. Diabetes Technology & Therapeutics, 2013. 15(2): p. 180–192.23360424
14 Conry, M.C., ., A 10 year (2000-2010) systematic review of interventions to improve quality of care in hospitals. BMC health services research, 2012. 12: p. 275.22925835
15 Coory, M., ., Systematic review of quality improvement interventions directed at cancer specialists. Journal of clinical oncology : official journal of the American Society of Clinical Oncology, 2013. 31(12): p. 1583–1591.23530093
16 Crema, M. and C. Verbano, Investigating the connections between health lean management and clinical risk management. International Journal of Health Care Quality Assurance (09526862), 2015. 28(8): p. 791–811.
17 Curatolo, N., ., A critical analysis of Lean approach structuring in hospitals. Business Process Management Journal, 2014.
18 Davidson, K., A. Perry, and L. Bell, Would continuous feedback of patient’s clinical outcomes to practitioners improve NHS psychological therapy services? Critical analysis and assessment of quality of existing studies. Psychology & Psychotherapy: Theory, Research & Practice, 2015. 88(1): p. 21–37.
19 Deblois, S. and L. Lepanto, Lean and Six Sigma in acute care: a systematic review of reviews. International journal of health care quality assurance, 2016. 29(2): p. 192–208.26959898
20 Dilley, J.A., B. Bekemeier, and J.R. Harris, Quality improvement interventions in public health systems: a systematic review. American journal of preventive medicine, 2012. 42(5 Suppl 1): p. S58–71.22502926
21 Donnellan, D., ., The effect of thermoregulation quality improvement initiatives on the admission temperature of premature/very low birth‐weight infants in neonatal intensive care units: A systematic review. Journal for Specialists in Pediatric Nursing, 2020. 25(2): p. 1–13.
22 Fry, T.J., S. Marfurt, and S. Wengier, Systematic Review of Quality Improvement Initiatives Related to Cue-Based Feeding in Preterm Infants. Nursing for women’s health, 2018. 22(5): p. 401–410.
23 Gallagher, H., ., Quality-improvement strategies for the management of hypertension in chronic kidney disease in primary care: a systematic review. The British journal of general practice : the journal of the Royal College of General Practitioners, 2010. 60(575): p. e258–265.20529489
24 Gao, T. and B. Gurd, Organizational issues for the lean success in China: exploring a change strategy for lean success. BMC health services research, 2019. 19(1): p. 66.30678663
25 Gettel, C.J., N. Pertsch, and E.M. Goldberg, A Systematic Review of Interventions to Improve Nursing Home to Emergency Department Care Transitions. Annals of Long Term Care, 2020. 28(2): p. e12–s4.32542070
26 Green, T., ., Use and reporting of experience-based codesign studies in the healthcare setting: a systematic review. BMJ Quality & Safety, 2020. 29(1): p. 64–76.
27 Hansen, L.O., ., Interventions to reduce 30-day rehospitalization: a systematic review. Annals of internal medicine, 2011. 155(8): p. 520–528.22007045
28 Healy, H., ., A systematic review of reports of quality improvement for bronchopulmonary dysplasia. Seminars in fetal & neonatal medicine, 2021: p. 101201.33563565
29 Henrique, D.B., & Godinho Filho, M., A systematic literature review of empirical research in Lean and Six Sigma in healthcare. Total Quality Management & Business Excellence, 2018: p. 1–21.
30 Irwin, R., T. Stokes, and T. Marshall, Practice-level quality improvement interventions in primary care: a review of systematic reviews. Primary Health Care Research & Development (Cambridge University Press / UK), 2015. 16(6): p. 556–577.
31 Ivers, N., ., Audit and feedback: effects on professional practice and healthcare outcomes. Cochrane Database of Systematic Reviews, 2012(6).
32 Jabin, M.S.R., ., A Mixed-Methods Systematic Review of the Effectiveness and Experiences of Quality Improvement Interventions in Radiology. Journal of patient safety, 2020.
33 Jesus, T.S., ., Key Characteristics of Rehabilitation Quality Improvement Publications: Scoping Review From 2010 to 2016. Archives of Physical Medicine & Rehabilitation, 2018. 99(6): p. 1141–1148.e4.28965737
34 Kampstra, N.A., ., Health outcomes measurement and organizational readiness support quality improvement: a systematic review. BMC health services research, 2018. 18(1): p. 1005.30594193
35 Kelendar, H., ., The use of lean methodology in healthcare settings in developing countries: a narrative review. British Journal of Healthcare Management, 2020. 26(6): p. 1–13.
36 Keller, S.C., ., Ambulatory Antibiotic Stewardship through a Human Factors Engineering Approach: A Systematic Review. Journal of the American Board of Family Medicine : JABFM, 2018. 31(3): p. 417–430.29743225
37 Knudsen, S.V., ., Can quality improvement improve the quality of care? A systematic review of reported effects and methodological rigor in plan-do-study-act projects. BMC health services research, 2019. 19(1): p. 683.31585540
38 Kourtis, S.A. and J.P. Burns, Quality improvement in pediatric intensive care: A systematic review of the literature. Pediatric investigation, 2019. 3(2): p. 110–116.32851301
39 Lamontagne, M.-E., ., A Scoping Review of Clinical Practice Improvement Methodology Use in Rehabilitation. Rehabilitation Process & Outcome, 2016(5): p. 1–11.
40 Marang-van de Mheen, P.J. and L. van Bodegom-Vos, Meta-analysis of the central line bundle for preventing catheterrelated infections: a case study in appraising the evidence in quality improvement. BMJ Quality & Safety, 2016. 25(2): p. 118–129.
41 Maurer, N.R., T.H. Hogan, and D.M. Walker, Hospital- and System-Wide Interventions for Health Care-Associated Infections: A Systematic Review. Medical care research and review : MCRR, 2020: p. 1077558720952921.
42 McPheeters, M.L., ., Quality improvement interventions to address health disparities: closing the quality gap - revisiting the state of the science. 2012: Centre for Reviews and Dissemination (UK).
43 Mery, G., ., Evaluating investment in quality improvement capacity building: a systematic review. BMJ open, 2017. 7(2): p. e012431.
44 Mileski, M., ., An investigation of quality improvement initiatives in decreasing the rate of avoidable 30-day, skilled nursing facility-to-hospital readmissions: a systematic review. Clinical interventions in aging, 2017. 12: p. 213–222.28182162
45 Mohandas, A., ., Role of Quality Improvement in Prevention of Inappropriate Transfusions. Quality Management in Health Care, 2011. 20(4): p. 298–310.21971027
46 Nayak, S. and S.L. Greenspan, How Can We Improve Osteoporosis Care? A Systematic Review and Meta-Analysis of the Efficacy of Quality Improvement Strategies for Osteoporosis. Journal of bone and mineral research : the official journal of the American Society for Bone and Mineral Research, 2018. 33(9): p. 1585–1594.
47 Neo, J.R.J., ., Evidence-Based Strategies in Using Persuasive Interventions to Optimize Antimicrobial Use in Healthcare: a Narrative Review. Journal of Medical Systems, 2020. 44(3): p. 1–13.
48 Ng, G.K.B., ., Factors affecting implementation of accreditation programmes and the impact of the accreditation process on quality improvement in hospitals: a SWOT analysis. Hong Kong Medical Journal = Xianggang Yi Xue Za Zhi, 2013. 19(5): p. 434–446.24088588
49 Nuckols, T.K., ., Economic Evaluation of Quality Improvement Interventions Designed to Improve Glycemic Control in Diabetes: A Systematic Review and Weighted Regression Analysis. Diabetes care, 2018. 41(5): p. 985–993.29678865
50 Nuckols, T.K., ., Economic Evaluation of Quality Improvement Interventions for Bloodstream Infections Related to Central Catheters: A Systematic Review. JAMA internal medicine, 2016. 176(12): p. 1843–1854.27775764
51 Olisemeke, B., ., The Effectiveness of Service Delivery Initiatives at Improving Patients’ Waiting Times in Clinical Radiology Departments: A Systematic Review. Journal of Digital Imaging, 2014. 27(6): p. 751–778.24888629
52 Parikh, K., S. Keller, and S. Ralston, Inpatient Quality Improvement Interventions for Asthma: A Meta-analysis. Pediatrics, 2018. 141(5): p. 1–15.
53 Patel, P. and G. Mitera, A Systematic Scoping Literature Review of Incorporating a Total Quality Culture Within Radiotherapy Staffing Models: A Management Strategy to Improve Patient Safety and Quality of Care in Radiation Therapy Departments. Journal of Medical Imaging & Radiation Sciences, 2011. 42(2): p. 81–85.31051853
54 Peimbert-García, R.E., Analysis and Evaluation of Reviews on Lean and Six Sigma in Health Care. Quality Management in Health Care, 2019. 28(4): p. 229–236.31567846
55 Perla, R.J., E. Bradbury, and C. Gunther-Murphy, Large-Scale Improvement Initiatives in Healthcare: A Scan of the Literature. Journal for Healthcare Quality: Promoting Excellence in Healthcare, 2013. 35(1): p. 30–40.
56 Reynolds, C., E. Esrailian, and D. Hommes, Quality Improvement in Gastroenterology: A Systematic Review of Practical Interventions for Clinicians. Digestive diseases and sciences, 2018. 63(10): p. 2507–2518.30014225
57 Sales, A.E., ., The use of data for process and quality improvement in long term care and home care: a systematic review of the literature. Journal of the American Medical Directors Association, 2012. 13(2): p. 103–113.21450243
58 Schouten, L.M., R.P. Grol, and M.E. Hulscher, Factors influencing success in quality-improvement collaboratives: development and psychometric testing of an instrument. Implement Sci, 2010. 5: p. 84.21029464
59 Silver, S.A., ., Effectiveness of Quality Improvement Strategies for the Management of CKD: A Meta-Analysis. Clinical journal of the American Society of Nephrology : CJASN, 2017. 12(10): p. 1601–1614.28877926
60 Soban, L.M., ., Preventing pressure ulcers in hospitals: a systematic review of nurse-focused quality improvements interventions. Joint Commission Journal on Quality & Patient Safety, 2011. 37(6): p. 245–252.21706984
61 Terens, N., ., Quality improvement strategies at primary care level to reduce inequalities in diabetes care: an equity-oriented systematic review. BMC endocrine disorders, 2018. 18(1): p. 31.29843692
62 Tricco, A.C., ., Effectiveness of quality improvement strategies for coordination of care to reduce use of health care services: a systematic review and meta-analysis. CMAJ : Canadian Medical Association journal = journal de l’Association medicale canadienne, 2014. 186(15): p. E568–578.
63 Vos, L., ., Towards an organisation-wide process-oriented organisation of care: a literature review. Implement Sci, 2011. 6: p. 8.21247491
64 Walker, C., Strategies for Improving Patient Throughput in an Acute Care Setting Resulting in Improved Outcomes: A Systematic Review. Nursing Economic$, 2016. 34(6): p. 277–288.29975490
65 Ward, K., ., Strategies to improve vaccination uptake in Australia, a systematic review of types and effectiveness…[corrected] [published erratum appears in AUST NZ J PUBLIC HEALTH 2012; 36(5):490]. Australian & New Zealand Journal of Public Health, 2012. 36(4): p. 369–377.
66 Wells, S., ., Are quality improvement collaboratives effective? A systematic review. BMJ quality & safety, 2018. 27(3): p. 226–240.
67 Williams, S., S. Keogh, and C. Douglas, Improving paediatric pain management in the emergency department: An integrative literature review. International Journal of Nursing Studies, 2019. 94: p. 9–20.30928719
68 Worswick, J., ., Improving quality of care for persons with diabetes: an overview of systematic reviews - what does the evidence tell us? Systematic reviews, 2013. 2: p. 26.23647654
69 Xie, A. and P. Carayon, A systematic review of human factors and ergonomics (HFE)-based healthcare system redesign for quality of care and patient safety. Ergonomics, 2015. 58(1): p. 33–49.25323570

## Not a Systematic Review, n=21

1 Beyranvand, T., A. Aryankhesal, and A. Aghaei Hashjin, Quality improvement in hospitals’ surgery-related processes: A systematic review. Medical journal of the Islamic Republic of Iran, 2019. 33: p. 129.32280635
2 Brackett, T., L. Comer, and R. Whichello, Do Lean Practices Lead to More Time at the Bedside? Journal for Healthcare Quality: Promoting Excellence in Healthcare, 2013. 35(2): p. 7–14.
3 Brennan, S., ., Continuous quality improvement: effects on professional practice and healthcare outcomes. Cochrane Database of Systematic Reviews, 2009(4).
4 Costa, L.B.M. and M. Godinho Filho, Lean healthcare: review, classification and analysis of literature. Production Planning & Control, 2016. 27(10): p. 823–836.
5 De Souza, L.B., Trends and approaches in lean healthcare. Leadership in health services, 2009.
6 de Souza, L.B. and M. Pidd, Exploring the barriers to lean health care implementation. Public Money & Management, 2011. 31(1): p. 59–66.
7 Hewson-Conroy, K.M., D. Elliott, and A.R. Burrell, Quality and safety in intensive care-A means to an end is critical. Australian Critical Care, 2010. 23(3): p. 109–129.20083413
8 Holden, R.J., Lean Thinking in emergency departments: a critical review. Ann Emerg Med, 2011. 57(3): p. 265–78.21035904
9 Honeycutt, L.C. and S.D. Keller, Effectiveness of the Lean process compared to other quality improvement initiatives on length of stay and wait times in healthcare organizations: a systematic review protocol. JBI database of systematic reviews and implementation reports, 2018. 16(1): p. 12–20.29324550
10 Kaplan, H.C., ., The Model for Understanding Success in Quality (MUSIQ): building a theory of context in healthcare quality improvement. BMJ Qual Saf, 2012. 21(1): p. 13–20.
11 Kim, C.S., ., Implementation of lean thinking: one health system’s journey. Jt Comm J Qual Patient Saf, 2009. 35(8): p. 406–13.19719076
12 Kollberg, B., J.J. Dahlgaard, and P.-O. Brehmer, Measuring lean initiatives in health care services: issues and findings. International Journal of Productivity and Performance Management, 2006. 56(1): p. 7–24.
13 Lukas, C.V., ., Transformational change in health care systems: an organizational model. Health Care Manage Rev, 2007. 32(4): p. 309–20.18075440
14 McIntosh, B. and G. Cookson, Lean management in the NHS: fad or panacea. British Journal of Healthcare Management, 2012. 18(3): p. 130–135.
15 Morrow, E., ., Emerald article: implementing large-scale quality improvement: lessons from The Productive Ward: Releasing Time to Care. 2012.
16 Poksinska, B., The current state of Lean implementation in health care: literature review. Qual Manag Health Care, 2010. 19(4): p. 319–29.20924253
17 Radnor, Z.J., M. Holweg, and J. Waring, Lean in healthcare: the unfilled promise? Soc Sci Med, 2012. 74(3): p. 364–371.21414703
18 Vest, J.R. and L.D. Gamm, A critical review of the research literature on Six Sigma, Lean and StuderGroup’s Hardwiring Excellence in the United States: the need to demonstrate and communicate the effectiveness of transformation strategies in healthcare. Implement Sci, 2009. 4: p. 35.19570218
19 Vituri, D.W. and Y.D. Martinez Évora, Total Quality Management and hospital nursing: an integrative literature review. Revista Brasileira de Enfermagem, 2015. 68(5): p. 660–667.
20 Walshe, K., Pseudoinnovation: the development and spread of healthcare quality improvement methodologies. Int J Qual Health Care, 2009. 21(3): p. 153–9.19383716
21 Walshe, K. and T. Freeman, Effectiveness of quality improvement: learning from evaluations. Qual Saf Health Care, 2002. 11(1): p. 85–7.12078378

## Unavailable, n=9

1 Abdallah, A.B. and R.Z. Alkhaldi, Lean bundles in health care: a scoping review. Journal of Health Organization & Management, 2019. 33(4): p. 488–510.31282812
2 Cacciatore, P., ., Lean thinking in the hospital setting - Results of a systematic review of literature. Igiene e sanita pubblica, 2019. 75(1): p. 29–50.31185489
3 DelliFraine, J.L., ., The use of six sigma in health care management: are we using it to its full potential? Quality Management in Health Care, 2013. 22(3): p. 210–223.23807133
4 DelliFraine, J.L., ., The Use of Six Sigma in Health Care Management: Are We Using It to Its Full Potential? Quality Management in Health Care, 2014. 23(4): p. 240–253.25260101
5 Hayward, L.M., How applicable is lean in mental health? A critical appraisal. International Journal of Clinical Leadership, 2012. 17(3): p. 166–173.
6 Khan, C. and G. Ollenschläger, [Effectiveness of quality assurance programmes for inpatient care in Germany: a literature review]. Zeitschrift fur Evidenz, Fortbildung und Qualitat im Gesundheitswesen, 2014. 108(10): p. 576–586.
7 Ralston, S., ., Effectiveness of quality improvement in hospitalization for bronchiolitis: a systematic review. Pediatrics, 2014. 134(3): p. 571–581.25092947
8 Taylor, M.J., ., Systematic review of the application of the plan-do-study-act method to improve quality in healthcare. BMJ Quality & Safety, 2014. 23(4): p. 290–298.
9 Vecchi, S., ., [Audit and feedback, and continuous quality improvement strategies to improve the quality of care for type 2 diabetes: a systematic review of literature]. Epidemiologia e prevenzione, 2016. 40(3-4): p. 215–223.27436255

## Duplicate, n=1

1 Wright Nunes, Julie, F. Jacob Seagull, Rao Panduranga, Jonathan H. Segal, Nandita S. Mani, Michael Heung, Julie Wright Nunes, and Panduranga Rao. 2016.‘Continuous quality improvement in nephrology: a systematic review’, BMC nephrology, 17: 190–90.27881093