# APPENDIX D PEER REVIEW DISPOSITION

Reviewer | Reviewer Comments | Author Responses
Executive Summary
2 | page 7, lines 8-9, not sure how being the largest integrated system is an incentive in and of itself to improve quality/safety. Not getting what aspect here is the incentive. | Edited to read, ‘As part of its mandate to optimize health outcomes for Veterans, the Department of Veterans Affairs (VA) has an incentive to improve the quality and safety of health care’. This was also changed in the Introduction.
2 | Lines 28-29, are both the Model for Change and Clinical Microsystems IHI’s? Thought clinical microsystems were another approach or model, but not IHI’s. Would be good to clarify. Actually, if both are IHI, no change would be needed. | Switched order of Model for Change and Clinical Microsystems to identify Model for Change as only IHI approach - ‘Clinical Microsystems or the Institute for Healthcare Improvement (IHI)’s Model for Change’
2 | page 8, why are DARE search dates truncated to 2015? | Bibliographic records published on DARE ceased at the end of March 2015. These databases can still be accessed but have not been and will not be updated.
2 | page 9, line 5, should add “and” before the final condition | Added as suggested
2 | Line 21-22, grammatical glitch, need to be either “had a modified AMSTAR2 rating” or “had modified AMSTAR2 ratings.” | Removed as suggested
2 | Line 34, should be “satisfaction was studied.” | Replaced as suggested
2 | page 10, line 19, need to decide on use of VA vs. VHA for consistency throughout (was VHA just a few lines above on line 11). | Changed to ‘VA’ throughout.
2 | Lines 23-24, would move “not” before the “with one exception” for ease in interpretation (have not, with one exception,…). | Moved as suggested
7 | Abbreviations Table: This review uses so many abbreviations – could you limit their use if word count is not an issue? Check the abbreviations table for “L = Lean” does not seem correct – pg. 4, line 58 | Thank you for your comment. We have reduced the abbreviations throughout.
7 | Could you explain an AMSTART2 rating of 2 (pg. 2, line 51) and the AMSTAR2 rating of 8 (pg. 3, line 23) (page 3, line 54) for I had to go looking for information in the text. | The following was added to the Executive Summary under Data Abstraction and Quality Assessment, ‘Each systematic review was assessed using a modified version of the Assessing the Methodological Quality of Systematic Reviews 2 (AMSTAR2) criteria ^4^. This 16-item tool was designed to assess the methodological quality of systematic reviews. As some AMSTAR2 items concern meta-analysis, we adapted the tool for this review, resulting in a 13-item tool. Assessment of studies using our modified tool was also completed in duplicate, with discrepancies resolved with group discussion. No study was excluded from analysis based on AMSTAR2 score; however, we chose a score of greater than or equal to 8 to represent higher quality systematic reviews. Studies based solely on qualitative analysis were not scored with the modified tool.’
7 | Please spell out/explain OECD countries and why this was pertinent for the review (page 4, line 10) | Added the following, ‘conducted in Organisation for Economic Co-operation and Development countries, which are a group of 38 countries with mature economies and, often, well-financed healthcare systems,’
7 | How many were performed with veteran populations (pg. 4, line 11)? | No SR was performed solely in veterans; however, individual studies often were performed in veteran populations. We did not track the full number of these included individual studies as part of this work. We did add ‘some individual studies were performed with Veteran populations, which improves applicability to VA’ earlier in the Discussion to clarify.
7 | You don’t abbreviate to CQI in first line of conclusion (pg. 4, line 23) or on lines 32, 35. I prefer it spelled out in the executive summary. | Removed CQI abbreviations from Executive Summary.
7 | Could you explain the publication bias (e.g., only successful studies were ultimately published (pg. 4, line 27)? | Added ‘as it is probable unsuccessful quality improvement work is less likely to receive publication’.
7 | Could you explain what a high AMSTAR 2 rating (e.g., 8 or higher) on pg. 4 line 38 | Please see comment above.
Introduction
2 | Page 12, lines 12-14, not sure of intent or meaning of “particularly in settings with fewer currently trained personnel…” As opposed to what? | Modified to the following, ‘particularly in settings such as individual clinics or units that may have fewer currently trained personnel to support project leadership and management’
7 | Could you expand on why Lean was selected by the VA in 2019? Was this because it is the most popular, or for other reasons (pg. 6, lines 27-28). Would help the reader appreciate why this review was requested after the decision was made (versus before). | Unfortunately, we do not have any information about the history of why Lean was selected by the VA beyond what was shared with us in the topic nomination brief.
Methods
2 | Page 14 (of document, appears to be page 8 of report, so other page references above are of the document itself), “rejected … publications that only reported components of QI without a full QI framework.” Could the authors clarify the volume of publications that fell in this category and consider the implications of not having a “full QI framework”? This phrase leaves me wondering what was left out and how much I should be concerned about it. | Since the scope of the review was to discuss CQI frameworks/methods, any publications that only mentioned components of QI (such as checklists, or audit and feedback) would not address either of the key questions and therefore were excluded from our review. Out of 165 publications excluded at abstract phase, 34 publications were excluded for not discussing a CQI framework/method. Some of these focused on specific QI components without an overarching framework or strategy, while others focused on interventions that did not describe themselves as CQI or match the description of CQI described by Rubenstein and colleagues (e.g., inhospital interventions to reduce diabetes readmissions).
2 | Lines 27-28, grammatical glitch “were not get assessed…” (take out word “get”). There are just enough of these kind of glitches that I recommend a thorough re-read by the authors to ensure they address any I missed. | Deleted this specific example, as well as further editing on full document
7 | Did you work with a librarian to validate the search method? | Yes, a librarian at the UCLA Library was one of our co-authors and team members. We added the following under the Search Strategy section, “Our team, which included a medical librarian, developed and conducted broad systematic review searches using terms…”
7 | What is the DARE database and why only searched until 2015? | Bibliographic records published on DARE ceased at the end of March 2015. These databases can still be accessed but have not been and will not be updated.
7 | Pg. 11 – line 11: You don’t abbreviate key questions – which is much better. Can you change the KQ in the figure 1 lit review to key questions and throughout the document? | We changed the abbreviations throughout.
Findings
2 | Literature flow, page 15, recommend past tense for “does not address key questions” etc. (line 11) since this section is otherwise in past tense. Same for line 13. | Changed as suggested
2 | Figure 1 typo lines 10-12 “de-depulication” ?? (assume they mean de-duplication). | Changed as noted
2 | What does RefMine mean? | RefMine stands for “reference mining.” It involves using bibliographies of a source to find more related sources. We have added language in text to clarify the addition of articles by reference mining, or “RefMine”.
2 | Would be helpful if Figure 2 was self-documenting (e.g., what is SS only? line 12). | Edited figure to reflect this.
2 | Page 19, line 50, typo “this has meant the even…” should be “that even”. Time spent on this level of a read is going to exceed time available, so urge authors to do a very careful read-through to remedy these grammatical and typographical errors throughout. | Changed as noted
2 | page 23, line 35, should be “reviewed implementation [in] emergency setting…” | Added as noted
2 | Line 55 “general categories of care” an e.g., would be helpful. | Added the following, ‘general categories of care, such as ‘productivity’ and ‘clinical quality’.
2 | page 25, lines 25-36 appears to be a single sentence and it is very hard to read through and stay on top of. | Regrettably, this may be a computer glitch. We apologize for the inconvenience!
3 | I would include as an appendix a table of all of the included studies with their respective quality ratings, broken down by criterion in other words, “show us the math” when it comes to the calculation of the quality rating for each study. The benefit of this is that, if necessary, a can be used in follow on analyses to more granularly assess the effect of these interventions (for example, via network meta-analysis; see comment #4 below)). Along related lines, p. 11 lists in text how many reviews received a given AMSTAR2 rating. This information is better conveyed through a histogram. | We have added a table with AMSTAR2 ratings, as well as more discussion of the scores.
4 | Minor issue on page 19: in the paragraph at the top of the page, a review is quoted as “having no more than 3.4 million defects per opportunity…” There is something wrong here, because it should be the other way around – not having more than 1 defect per 3.4 million opportunities | Thank you for noting this, as this was a direct quote from the referenced article. We have removed the quotations from this error and corrected the statement as follows, ‘as having no more than one defect per 3.4 million opportunities ‘may not be realistic or applicable to many QI issues faced by health care organizations‘.
5 | Page 10, Figure 1 - RefMine is included in the figure but it not referenced in the text. Please explain the addition of articles by RefMine in the literature flow. | We have added language in text to clarify the addition of articles by reference mining, or “RefMine”.
7 | Pg. 13, line 37: Can you explain reference mining and why this article was not captured using the review methods? | We have added language in text to clarify the addition of articles by reference mining, or “RefMine”. The article in question was identified by reference mining and not our searches because it was published prior to the dates specified in our search. Given that our search did not identify any literature within the desired time frame addressing KQ1A, this publication merited inclusion despite its age.
7 | Pg. 17, line 26 – which National Health Service? Same on Pg. 18., lines 34-45 | The UK National Health Service; we have inserted this in the report.
7 | Pg. 19, line 37 – double negative is hard to read | We have revised this sentence.
7 | Pg. 20, line 27 – what is a QIC? At this point I’m so overwhelmed by the abbreviations… | QIC is Quality Improvement Collaborative. We have streamlined the number of abbreviations throughout for readability.
7 | Pg 23, line 26: typo “review” not reviewed | Edited to read as follows, ‘reviewed the included articles’
7 | Pg 25, line 45 – typo – check font on multiple strategies | Regrettably, this may be a computer glitch. We apologize for the inconvenience!
7 | Page 26, line 51 – mention why the five articles were not rated using the AMSTART2 | We provided explanation in text.
7 | Page 27, line 21-22. The sentence “no systematic reviews addressed Veterans” is confusing. I’m assuming you mean there was not a specific review that focused exclusively on Veterans or VHA, but there were a couple studies that were VA based included. Rewording would help comprehension. | Reworded to the following, ‘No systematic reviews specifically addressed care of Veterans as a study objective nor were any conducted fully in VA settings, although several individual articles within the included systematic reviews were based at VA
Discussion
3 | This may be an issue of systematic review writing style, but I could have done with a bit more discussion, reflection, interpretation, and recommendations for future directions. For example, one of the most important points I think that the authors make is the idea that there seems to be no one best way to conduct quality improvement in an organization. That is certainly consistent with current frameworks and implementation science, as well as general theries of organizational development and change. And this is a conclusion that really stands beyond the Powell et al. 2008 study; this conclusion is appropriately reached by the preponderance of evidence of a single studies of the studies that tested the effectiveness of single interventions as well. | We have expanded the following sections: Limitations, Study Quality, Applicability to VA, Research Gaps/Future Research, and Conclusions.
3 | In another part of the conclusions the authors state: “Few systematic reviews included in this review of reviews had high ratings on a modified AMSTAR2 tool, leading us to conclude the overall quality of evidence related to these topics is low-to-moderate.” Why is that? Why are so many QI studies of low to moderate quality? The cynic might answer, “because there was no IRB holding these QI teams to the rigorous standards of research.” A more pragmatic answer, however, is likely that change is messy. In other words quality improvement must be tested in situ, not a laboratory, in order to fully understand its effectiveness in this setting question. Certainly the aforementioned suggestion to include the breakdown of quality ratings by criterion for each study (see comment #1, above) would be helpful in better understanding what is going on with respect to study quality. | We have renamed the ‘Study Quality’ section ‘Quality of Included Reviews’ to clarify that we are not referring to quality of individual studies but rather, overall quality of systematic reviews. We have expanded this point, which now reads, ‘These low ratings on the AMSTAR2 tool leads us to conclude the overall certainty of evidence related to these reviews is low-to-moderate.’ Reasons for the low AMSTAR2 scores of identified reviews may include underlying issues with study design and implementation in the primary QI literature, as well as with study reporting. Most QI initiatives are designed and implemented in pragmatic clinical or operational settings, which may limit overall study quality for inclusion into a systematic review. Even when sufficient elements are included in QI projects, however, the elements may not be fully explained in subsequent manuscripts. These issues may then be compounded in performing and reporting systematic reviews.’; We have also added a table re: AMSTAR2 information (Table 2).
3 | Related to the study quality and future directions points, perhaps an appropriate future direction is to adopt a more meta-analytic approach to answering these evidence synthesis questions. In other words, (to be clear: not for the systematic review, but rather for the follow on study that should come next) the suggestion is to be analyze the included studies (and since this is a review of reviews, I would go so far as to say to use the original empirical studies included in the reviews examined) according to their individual study quality characteristics, and try to come up with some effect sizes with study quality accounted for. This approach is in many ways a analogous to the Hunter and Schmidt style of meta-analysis, which in psychological studies accounts for the reliability and validity of the criterion and predictor variables of each study as moderators and the overall meta-analysis, thereby yielding a more nuanced assessment of effect size. | This section has been expanded to now include, ‘The most notable of these gaps is a lack of comparative studies analyzing multiple continuous quality improvement methodologies within healthcare settings. Although such comparative examples may be identifiable in other fields, such as manufacturing, the complexity of healthcare processes and the variability in local contexts for implementation of QI methodologies within healthcare warrants creation of such studies. As noted above, current VA efforts from resources such as the EBQI or LEAP programs may provide opportunities to promote such comparative investigations. An alternative approach would be to attempt meta-analysis of multiple continuous quality improvement methodologies with narrow questions in specific settings from the existing primary literature, such as waiting times in emergency departments. However, given the limitations of the systematic reviews in our review of reviews, such an initiative would likely require sharing and re-analysis of the primary data from the original studies.’
4 | On page 29, the section on “Research Gaps/Future Research” seems underdeveloped. It would be helpful to go on to provide detail about the “several gaps” noted in the one sentence in that section, which seems like it should be a topic sentence of a full paragraph. | Please see the above response.
7 | Since the only paper describing comparative effectiveness was found using reference mining because it was a report and not indexed, you should address how this may have impacted your overall findings | This study was identified via reference mining as it was excluded from original searches given its age. We have added the following to highlight this, ‘The single study explicitly discussing comparative effectiveness was identified via reference mining given its age. We chose to include this article, despite not making our publication date cut-off, as it was the only study we identified directly address the first Key Question.’
7 | Pg. 28, line 5-6: can you explain why OECD countries improves the applicability to VHA? | We have added the following, ‘Organisation for Economic Co-operation and Development (OECD) countries, which generally have well-funded healthcare systems and improves applicability to VA’.
7 | Research gaps/future research: Pg 29, lines 17-19 -This is where work from outside healthcare would be beneficial. Could you briefly look to see if other industries have compared CQI methods. If yes, which came out on top. If no, can you include possible reasons why this work is challenging and research methods that could address these questions. | This is an important note, although we feel work from outside healthcare is likely ungeneralizable into a healthcare context given the difference in contexts and outcomes and complexity of healthcare workflows. We did attempt to address this point as follows, ‘The most notable of these gaps is a lack of comparative studies analyzing multiple continuous quality improvement methodologies within healthcare settings. Although such comparative examples may be identifiable in other fields, such as manufacturing, the complexity of healthcare processes and the variability in local contexts for implementation of QI methodologies within healthcare warrants creation of such studies.
5 | However, the conclusion is unsatisfying as it leaves the reader without a map for next steps. What are the next steps from here? What is a reader to do if one wants to determine the most effective improvement methodology? Consider adding to the discussion if there are comparative effectiveness studies of continuous quality improvement outside of healthcare. Can we learn something from another industry about reporting on CQI that we can apply in future effectiveness studies of CQI in healthcare? | Please see the amended section and comment above.
General/Misc.
1 | Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?: Yes - Work by Michael Parchman on Practice Facilitation REview QUERI Learning Hubs to determine if any of them also provide training in QI methodologies- notably LEAP, EBQI, Quality Scholars, Facilitation, LOCI, etc- see full list here: https://www.queri.research.va.gov/training_hubs/default.cfm Conceptual work by Friedman on the Learning Health System cycle | One article of Dr. Parchman’s was included in a systematic review we included in this study (Hill, 2020). However, as he has not performed any systematic reviews, these other works would not have been eligible for inclusion in this project. Such issues with literature inclusion/scope are certainly limitations of the review of reviews approach, as we have emphasized in the Limitations as follows, ‘Similarly, one limitation of the review of reviews approach is an inability to closely align the inclusion criteria or scopes of the individual systematic reviews’. We have added the following to the ‘Applicability of Findings to the VA Population’ section, ‘Within VA, there are several ongoing initiatives that use continuous quality improvement methodologies or frameworks with continuous quality improvement elements, such as the Evidence-Based Quality Improvement (EBQI) Training Hub and The Learn. Engage. Act. Process. (LEAP) Program, in addition to the focus on Lean in systems redesign. These current efforts may not be represented universally in the published literature, nor were any of these initiatives specifically identified in the systematic reviews that comprised this review of reviews, limiting our ability to discuss comparisons with other strategies. However, these initiatives may provide opportunities for comparative evaluations of continuous quality improvements methods.’; We also added the following to the Conclusions, ‘Future work should emphasize comparative designs for continuous quality improvement methodologies. Available resources at VA may help facilitate such work in the future.’
1 | This is a very thorough review. The authors should also consider framing their findings within the context of current VHA initiatives around knowledge translation and HRO, which are part of the VHA Long-range goal of innovating as a learning and teaching organization. For example, it might be good to see which program offices (e.g., QUERI training programs, NCPS, NCOD, etc) are training others or using some of the ‘necessary, but not sufficient’ conditions for successful implementation of CQI: human resources, provider (MD) involvement), sustained managerial focus, etc. etc | Please see the latter half of the above comment.
2 | Minor comment on TEP: Dr. Godwin is not just at Baylor -- she is a VA researcher as well, and leads the National VA Quality Scholars Coordinating Center. Unintentionally may misrepresent her as unattached to VA. May want to consider adding her VA title and adding academic titles to other TEP members as well. Small thing is that you refer to some folks as being from the VA Greater LA Healthcare System but describe the ESP as not. May want to consider adding GLA to the WLA reference. | We have edited this section to reflect the appropriate titles, thank you!
2 | Minor comment on Peer Reviewers: When I have been a TEP member on this and other ESP reports, it is not uncommon for me to be asked to peer review the report as well. So when I see the section on peer reviewers, it makes me wonder if those are indeed the same as TEP or a mix of TEP and non-TEP. Might be useful to clarify. | Thank you for your comment. We have added, ‘Technical Panel Experts are often asked to also serve as peer reviewers, but we also invite experts who have not been involved with the current project to serve as peer reviewers.’
2 | A brief summary of what the improvements would be might be helpful to make it easier for other professionals in this space to refer to when designing, conducting, and writing up their work - actually, given that such guidelines exist, the authors may want to add a sentence about re-emphasizing their use in the field. The report would benefit from a very careful re-read by one of the authors for typos/grammatical glitches. I worked to include all I saw but may not have caught them all. | We have added the following to the Research Gaps / Future Research section, ‘The overall evidence base would be improved if future reported individual QI studies more closely adhered to SQUIRE 2.0 reporting standards. Similarly, future systematic reviews of these works would be stronger by considering the AMSTAR2 categories we found to be often lacking, such as specifying comparators as an inclusion criteria and sharing the results of comparators from individual trials, PROSPERO registration, and explicitly discussing risk of bias.’
2 | page 21, lines 46, reference to “trust pharmacies” and “trust systems” -- suspect these are from NHS type system but for a US readership, it would be helpful to add a definition or e.g., or something. Similarly, it would be helpful if the authors did a read-through/search to make sure that each abbreviation is spelled out on first use. There is inconsistency in how this is handled (e.g., ED vs. emergency department) - many of these are not in the table of abbreviations, which is fine because you do not want readers to have to continue to go back to the table frequently. There are also variations in tense that warrant attention, e.g., page 22, line 7, two studies…”look at Lean strategies,” while the next section is past tense “both review found…” | Your intuition was correct and we have added ‘National Health Service’ to clarify the language around trusts. Thank you for the other careful edits – we have clarified the abbreviations and abbreviations table and attempted to clear the remainder of the typos with this draft.
2 | Ref #1 is incomplete. I did not go through the rest but omission on the 1st reference suggests all should be re-reviewed for completeness. | Thank you for your comment. We have reviewed all references.
3 | I would also try to model the behavior the authors lamented being absent in some of the studies that they themselves review: put together an AMSTAR2 checklist and use it as a reporting standards checklist for this review of reviews (the same way one would include a PRISMA checklist for a meta-analysis | Thank you for your suggestion. We are unaware of the existence of such a tool for a review of reviews. We have included in our report the areas that may apply from the AMSTAR2 tool, such as registration of our protocol and duplicate data collection. However, as many aspects of AMSTAR2, such as the appropriateness of meta-analytic techniques and risk of bias for included primary studies, do not apply to a review of reviews, we have created a list.
3 | If resources and the structure of the reporting mechanism allow, it might be nice to create a more interactive version of this Appendix E table by which users could sort and filter that could be made available in addition. | Thank you for your comment. While a very interesting idea, we are unable to add interactive features to the reports at this time.
4 | When I first read Key Questions 1A and 1B, I was unclear on how they differed (and may still be a bit unclear now). It seems like Key Question 1B still involved looking for indirect comparisons of effectiveness (at least, conclusions by authors of the studied systematic reviews regarding differential evidence of effectiveness between Lean and Six Sigma). For example, on page 15 (part of question 1B), it is noted that “None of the 11 reviews that included more than one CQI strategy reached a strong conclusion that any strategy was superior to any other(s).” If I understand Key Question 1A correctly, eligible reviews had to have to actually have comparative effectiveness as their stated focus? If the authors could do more to clarify the criteria for deciding how a study became eligible for Key Question 1A as opposed to being in Key Question 1B, that would be helpful. | This is correct. We attempted to clarify under Topic Development, as follows, ‘To be eligible for Key Question 1A, a systematic review had to explicitly focus on comparative effectiveness of multiple continuous quality improvement methodologies as a stated aim. If a review commented on multiple methodologies but did not seek to compare the effectiveness of the strategies within its methods, it was included in Key Question 1B.’
4 | Given how frequently Lean and Six Sigma are discussed in the report, it would be helpful to provide a brief description of what constitutes a Lean approach or a Six Sigma approach. The directive to use Lean makes it important to define (in general terms) what constitutes a Lean approach, and since Six Sigma is one of the most popular alternatives to Lean, a brief definition of Six Sigma would be helpful as well. | We did not explicitly define each method for our search strategy, as we allowed each systematic review to categorize the included individual studies as the authors had chosen originally. This is now emphasized in the Study Selection section, ‘Specific definitions for each strategy were not included in our search strategy; rather, we allowed each systematic review to apply its own definitions to the included studies.’
7 | Pg 7, lines 56-59: A table listing the CQI strategies with a brief definition of each approach would enhance the readers understanding of each method. Appendix B does not include this information. | Please see above comment and response. We did not define strategies for this review of reviews and individual studies had considerable variability in their own definitions/discussion of strategies.
7 | The big question is if any work has been done outside healthcare? The review was comprehensive but inconclusive. Is there knowledge from other fields that could inform healthcare? If yes, it should be briefly included in the review. If no, perhaps address why there is not work comparing CQI methods?; Omitted evidence; - Work outside of healthcare; - Non-indexed program reports | Please see our earlier comment about work outside healthcare having poor generalizability to the healthcare context. We have expanded comments about other VA work that may help to answer these questions in the future, in addition to the expanded Research Gaps previously mentioned.