# APPENDIX A SEARCH STRATEGIES

DATABASE SEARCHED & TIME PERIOD COVERED:

PubMed – From 01/01/2010 to 03/18/2021

SEARCH STRATEGY: 879 results

(Total Quality Management[MESH] OR Quality Improvement[Mesh]) OR (CQI[Title/Abstract] OR “Continuous Quality Improvement”[Title/Abstract] OR “Quality Improvement” [Title/Abstract] OR “Lean Six Sigma”[Title/Abstract] OR “Clinical MicroSystems”[Title/Abstract] OR “Model for Improvement”[Title/Abstract] OR “lean management”[Title/Abstract] OR “lean thinking”[Title/Abstract] OR “lean healthcare”[Title/Abstract] OR “lean principles“[Title/Abstract] OR Toyota[Title/Abstract] OR IHI[Title/Abstract])

----------------------------------------------------------------------------------------

DATABASE SEARCHED & TIME PERIOD COVERED:

CINAHL – From 01/01/2010 to 03/30/2021

SEARCH STRATEGY: 1068 results

MH Quality Improvement OR TI (CQI OR “Continuous Quality Improvement” OR “Quality Improvement” OR “Lean Six Sigma” OR “Clinical MicroSystems” OR “Model for Improvement” OR “lean management” OR “lean thinking” OR “lean healthcare” OR “lean principles” OR Toyota OR IHI OR “system redesign” OR Total Quality Management”) OR AB (CQI OR “Continuous Quality Improvement” OR “Quality Improvement” OR “Lean Six Sigma” OR “Clinical MicroSystems” OR “Model for Improvement” OR “lean management” OR “lean thinking” OR “lean healthcare” OR “lean principles” OR Toyota OR IHI OR “system redesign” OR “Total Quality Management”)

----------------------------------------------------------------------------------------

DATABASE SEARCHED & TIME PERIOD COVERED:

DARE – From 01/01/2010 to 03/31/2015

SEARCH STRATEGY: 78 results

MeSH descriptor: [Quality Improvement]

OR

(CQI OR “Continuous Quality Improvement” OR “Quality Improvement” OR “Lean Six Sigma” OR “Clinical MicroSystems” OR “Model for Improvement” OR “lean management” OR “lean thinking” OR “lean healthcare” OR “lean principles” OR Toyota OR IHI OR “system redesign” OR “Total Quality Management”)

----------------------------------------------------------------------------------------

DATABASE SEARCHED & TIME PERIOD COVERED:

Cochrane – From 01/01/2010 to 03/30/2021

SEARCH STRATEGY: 54 results

MeSH descriptor: [Quality Improvement]

OR

(CQI OR “Continuous Quality Improvement” OR “Quality Improvement” OR “Lean Six Sigma” OR “Clinical MicroSystems” OR “Model for Improvement” OR “lean management” OR “lean thinking” OR “lean healthcare” OR “lean principles” OR Toyota OR IHI OR “system redesign” OR “Total Quality Management”)