# REFERENCES

1 Treede RD, Rief W, Barke A, . Chronic pain as a symptom or a disease: the IASP Classification of Chronic Pain for the International Classification of Diseases (ICD-11). Pain. 2019;160(1):19–27.30586067
2 Department of Veterans Affairs/Department of Defense. VA/DoD Clinical Practice Guideline for the Management of Concussion-Mild Traumatic Brain Injury. Washington, DC 2016.
3 Abel EA, Brandt CA, Czlapinski R, Goulet JL. Pain research using Veterans Health Administration electronic and administrative data sources. J Rehabil Res Dev. 2016;53(1):1–12.27005814
4 Seal KH, Bertenthal D, Barnes DE, . Association of Traumatic Brain Injury With Chronic Pain in Iraq and Afghanistan Veterans: Effect of Comorbid Mental Health Conditions. Arch Phys Med Rehabil. 2017;98(8):1636–1645.28455190
5 Carlson KF, Barnes JE, Hagel EM, Taylor BC, Cifu DX, Sayer NA. Sensitivity and specificity of traumatic brain injury diagnosis codes in United States Department of Veterans Affairs administrative data. Brain Inj. 2013;27(6):640–650.23514276
6 Ruff RL, Ruff SS, Wang XF. Headaches among Operation Iraqi Freedom/Operation Enduring Freedom veterans with mild traumatic brain injury associated with exposures to explosions. J Rehabil Res Dev. 2008;45(7):941–952.19165684
7 Pugh MJ, Swan AA, Amuan ME, . Deployment, suicide, and overdose among comorbidity phenotypes following mild traumatic brain injury: A retrospective cohort study from the Chronic Effects of Neurotrauma Consortium. PLoS ONE. 2019;14(9):e0222674.31539410
8 VHA Office of Mental Health and Suicide Prevention. VA National Suicide Data Report 2005–2016. September 2018.
9 VHA Office of Mental Health and Suicide Prevention. National Strategy for Preventing Veteran Suicide 2018–2028. 2018.
10 Byers AL, Li Y, Barnes DE, Seal KH, Boscardin WJ, Yaffe K. A national study of TBI and risk of suicide and unintended death by overdose and firearms. Brain Inj. 2020;34(3):328–334.31822136
11 Madsen T, Erlangsen A, Orlovska S, Mofaddy R, Nordentoft M, Benros ME. Association Between Traumatic Brain Injury and Risk of Suicide. Jama. 2018;320(6):580–588.30120477
12 Leung A, Shukla S, Fallah A, . Repetitive Transcranial Magnetic Stimulation in Managing Mild Traumatic Brain Injury-Related Headaches. Neuromodulation. 2016;19(2):133–141.26555886
13 Leung A, Metzger-Smith V, He Y, . Left Dorsolateral Prefrontal Cortex rTMS in Alleviating MTBI Related Headaches and Depressive Symptoms. Neuromodulation. 2018;21(4):390–401.28557049
14 Nelson DV, Esty ML. Neurotherapy for chronic headache following traumatic brain injury. Mil. 2015;2:22.
15 Hoge CW, McGurk D, Thomas JL, Cox AL, Engel CC, Castro CA. Mild traumatic brain injury in U.S. Soldiers returning from Iraq. N Engl J Med. 2008;358(5):453–463.
16 Defense and Veterans Brain Injury Center. DoD Worldwide Numbers for TBI. (2000–2019 Q3) Web site. https://dvbic.dcoe.mil/dod-worldwide-numbers-tbi. Published 2019. Accessed January 28, 2020.
17 Carroll LJ, Cassidy JD, Cancelliere C, . Systematic review of the prognosis after mild traumatic brain injury in adults: cognitive, psychiatric, and mortality outcomes: results of the International Collaboration on Mild Traumatic Brain Injury Prognosis. Arch Phys Med Rehabil. 2014;95:(3 Suppl):S152–173.24581903
18 O’Neil ME, Carlson KF, Storzbach D, . Factors Associated with Mild Traumatic Brain Injury in Veterans and Military Personnel: A Systematic Review. J Int Neuropsychol Soc. 2014:1–13.
19 Ruff R. Two decades of advances in understanding of mild traumatic brain injury. J Head Trauma Rehabil. 2005;20(1):5–18.15668567
20 Department of Veterans Affairs. Polytrauma System of Care. In: Veterans Health Administration, ed. Vol VHA Directive 1172.01. Washington, DC 2019.
21 Hendricks AM, Amara J, Baker E, . Screening for mild traumatic brain injury in OEF-OIF deployed US military: an empirical assessment of VHA’s experience. Brain Inj. 2013;27(2):125–134.23384211
22 Vanderploeg RD, Belanger HG. Screening for a remote history of mild traumatic brain injury: when a good idea is bad. J Head Trauma Rehabil. 2013;28(3):211–218.23661073
23 Hoge CW, Goldberg HM, Castro CA. Care of war veterans with mild traumatic brain injury-flawed perspectives. N Engl J Med. 2009;360(16):1588–1591.19369664
24 Vasterling JJ, Aslan M, Lee LO, . Longitudinal Associations among Posttraumatic Stress Disorder Symptoms, Traumatic Brain Injury, and Neurocognitive Functioning in Army Soldiers Deployed to the Iraq War. J Int Neuropsychol Soc. 2018;24(4):311–323.29199924
25 Lew HL, Otis JD, Tun C, Kerns RD, Clark ME, Cifu DX. Prevalence of chronic pain, posttraumatic stress disorder, and persistent postconcussive symptoms in OIF/OEF veterans: polytrauma clinical triad. J Rehabil Res Dev. 2009;46(6):697–702.20104399
26 Pagulayan KF, O’Neil M, Williams RM, . Mental Health Does Not Moderate Compensatory Cognitive Training Efficacy for Veterans With a History of Mild Traumatic Brain Injury. Arch Phys Med Rehabil. 2017;98(9):1893–1896.e1892.28483653
27 Irvine KA, Clark JD. Chronic Pain After Traumatic Brain Injury: Pathophysiology and Pain Mechanisms. Pain Med. 2018;19(7):1315–1333.29025157
28 Prevention VOoMHaS. 2019 National Veteran Suicide Prevention Annual Report. 2019.
29 Finley EP, Bollinger M, Noel PH, . A national cohort study of the association between the polytrauma clinical triad and suicide-related behavior among US Veterans who served in Iraq and Afghanistan. Am J Public Health. 2015;105(2):380–387.25033126
30 Hostetter TA, Hoffmire CA, Forster JE, Adams RS, Stearns-Yoder KA, Brenner LA. Suicide and Traumatic Brain Injury Among Individuals Seeking Veterans Health Administration Services Between Fiscal Years 2006 and 2015. J Head Trauma Rehabil. 2019;34(5):E1–e9.
31 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–46.27005575
32 Treadwell JR, Singh S, Talati R, McPheeters ML, Reston JT. A framework for best evidence approaches can improve the transparency of systematic reviews. J Clin Epidemiol. 2012;65(11):1159–1162.23017634
33 Higgins J, Savovic J, Page MJ, Sterne JA. Revised Cochrane risk-of-bias tool for randomized trials (RoB 2). https://methods.cochrane.org/bias/resources/rob-2-revised-cochrane-risk-bias-tool-randomized-trials. 2019.
34 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. 2016;355:i4919.27733354
35 Wells G, Shea B, O’Connell D, . The Newcastle-Ottawa Scale (NOS) for assessing the quality of nonrandomised studies in meta-analyses. http://www.ohri.ca/programs/clinical_epidemiology/oxford.asp. Accessed 1/31/2020.
36 Munn Z, Moola S, Riitano D, Lisy K. The development of a critical appraisal tool for use in systematic reviews addressing questions of prevalence. International journal of health policy and management. 2014;3(3):123–128.25197676
37 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. 2015;68(11):1312–1324.25721570
38 Atkins D, Chang SM, Gartlehner G, . Assessing applicability when comparing medical interventions: AHRQ and the Effective Health Care Program. J Clin Epidemiol. 2011;64(11):1198–1207.21463926
39 Kulas JF, Rosenheck RA. A Comparison of Veterans with Post-traumatic Stress Disorder, with Mild Traumatic Brain Injury and with Both Disorders: Understanding Multimorbidity. Mil Med. 2018;183(3–4):e114–e122.29514340
40 King PR, Wade MJ, Beehler GP. Health service and medication use among veterans with persistent postconcussive symptoms. J Nerv Ment Dis. 2014;202(3):231–238.24566509
41 Hoot MR, Levin HS, Smith AN, . Pain and chronic mild traumatic brain injury in the US military population: a Chronic Effects of Neurotrauma Consortium study. Brain Inj. 2018;32(10):1169–1177.29883191
42 Brickell TA, Lange RT, French LM. Health-related quality of life within the first 5 years following military-related concurrent mild traumatic brain injury and polytrauma. Mil Med. 2014;179(8):827–838.25102525
43 Powell MA, Corbo V, Fonda JR, Otis JD, Milberg WP, McGlinchey RE. Sleep Quality and Reexperiencing Symptoms of PTSD Are Associated With Current Pain in U.S. OEF/OIF/OND Veterans With and Without mTBIs. J Trauma Stress. 2015;28(4):322–329.
44 Romesser J, Booth J, Benge J, Pastorek N, Helmer D. Mild traumatic brain injury and pain in Operation Iraqi Freedom/Operation Enduring Freedom veterans. J Rehabil Res Dev. 2012;49(7):1127–1136.23341284
45 Beswick-Escanlar VP, Lee T, Hu Z, Clark LL. Increasing severity of traumatic brain injury is associated with an increased risk of subsequent headache or migraine: a retrospective cohort study of U.S. active duty service members, 2006–2015. Msmr. 2016;23(7):2–8.
46 Couch JR, Stewart KE. Headache Prevalence at 4–11 Years After Deployment-Related Traumatic Brain Injury in Veterans of Iraq and Afghanistan Wars and Comparison to Controls: A Matched Case-Controlled Study. Headache. 2016;56(6):1004–1021.27237921
47 Farrell-Carnahan L, Barnett S, Lamberty G, . Insomnia symptoms and behavioural health symptoms in veterans 1 year after traumatic brain injury. Brain Inj. 2015:1–9.
48 Jackson CE, Green JD, Bovin MJ, . Mild Traumatic Brain Injury, PTSD, and Psychosocial Functioning Among Male and Female U.S. OEF/OIF Veterans. J Trauma Stress. 2016;29(4):309–316.27405050
49 MacGregor AJ, Dougherty AL, Tang JJ, Galarneau MR. Postconcussive symptom reporting among US combat veterans with mild traumatic brain injury from Operation Iraqi Freedom. J Head Trauma Rehabil. 2013;28(1):59–67.22688214
50 Patil VK, St Andre JR, Crisan E, . Prevalence and treatment of headaches in veterans with mild traumatic brain injury. Headache. 2011;51(7):1112–1121.21762135
51 Schwab K, Terrio HP, Brenner LA, . Epidemiology and prognosis of mild traumatic brain injury in returning soldiers: A cohort study. Neurology. 2017;88(16):1571–1579.28314862
52 Suri P, Stolzmann K, Williams R, Pogoda TK. Deployment-Related Traumatic Brain Injury and Risk of New Episodes of Care for Back Pain in Veterans. J Pain. 2019;20(1):97–107.30172707
53 Suri P, Stolzmann K, Iverson KM, . Associations Between Traumatic Brain Injury History and Future Headache Severity in Veterans: A Longitudinal Study. Arch Phys Med Rehabil. 2017;98(11):2118–2125.e2111.28483652
54 Theeler BJ, Flynn FG, Erickson JC. Chronic daily headache in U.S. soldiers after concussion. Headache. 2012;52(5):732–738.22404747
55 Tsao JW, Stentz LA, Rouhanian M, . Effect of concussion and blast exposure on symptoms after military deployment. Neurology. 2017;89(19):2010–2016.29030450
56 Vanderploeg RD, Belanger HG, Curtiss G. Mild traumatic brain injury and posttraumatic stress disorder and their associations with health symptoms. Arch Phys Med Rehabil. 2009;90(7):1084–1093.19577020
57 Walker WC, Hirsch S, Carne W, . Chronic Effects of Neurotrauma Consortium (CENC) multicentre study interim analysis: Differences between participants with positive versus negative mild TBI histories. Brain Inj. 2018;32(9):1079–1089.29851515
58 Webb TS, Whitehead CR, Wells TS, Gore RK, Otte CN. Neurologically-related sequelae associated with mild traumatic brain injury. Brain Inj. 2015;29(4):430–437.25541640
59 Wilk JE, Herrell RK, Wynn GH, Riviere LA, Hoge CW. Mild traumatic brain injury (concussion), posttraumatic stress disorder, and depression in U.S. soldiers involved in combat deployments: association with postdeployment symptoms. Psychosom Med. 2012;74(3):249–257.22366583
60 Wilk JE, Thomas JL, McGurk DM, Riviere LA, Castro CA, Hoge CW. Mild traumatic brain injury (concussion) during combat: lack of association of blast mechanism with persistent postconcussive symptoms. J Head Trauma Rehabil. 2010;25(1):9–14.20051900
61 Walker WC, Nowak KJ, Kenney K, . Is balance performance reduced after mild traumatic brain injury?: Interim analysis from chronic effects of neurotrauma consortium (CENC) multi-centre study. Brain Inj. 2018;32(10):1156–1168.29894203
62 NIH study broadens understanding of High Impact Chronic Pain in the U.S. [press release]. September 5 2018.
63 Dismuke-Greer C, Hirsch S, Carlson K, . Health Services Utilization, Health Care Costs, and Diagnoses by Mild Traumatic Brain Injury Exposure: A Chronic Effects of Neurotrauma Consortium Study. Archives of Physical Medicine and Rehabilitation. 2020.
64 Taylor BC, Hagel EM, Carlson KF, . Prevalence and costs of co-occurring traumatic brain injury with and without psychiatric disturbance and pain among Afghanistan and Iraq War Veteran V.A. users. Med Care. 2012;50(4):342–346.22228249
65 Goulet JL, Kerns RD, Bair M, . The musculoskeletal diagnosis cohort: examining pain and pain care among veterans. Pain. 2016;157(8):1696–1703.27023420
66 Dworkin RH, Turk DC, Farrar JT, . Core outcome measures for chronic pain clinical trials: IMMPACT recommendations. Pain. 2005;113(1).
67 Turk DC, Dworkin RH, Allen RR, . Core outcome domains for chronic pain clinical trials: IMMPACT recommendations. Pain. 2003;106(3):337–345.14659516
68 Kroenke K, Krebs EE, Turk D, . Core Outcome Measures for Chronic Musculoskeletal Pain Research: Recommendations from a Veterans Health Administration Work Group. Pain Med. 2019;20(8):1500–1508.30615172