# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by the VHA Committee on the Care of Veterans with Traumatic Brain Injury (TBI) for an evidence review on the epidemiology, assessment, and treatment of chronic pain complicated by co-occurring mild traumatic brain injury (mTBI) in combat veterans. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Robin Paynter, MLIS, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Stuart Hoffman, PhD
  Scientific Program Manager, VA Office of Research and Development
  Veterans Health Administration, Washington, DC
- Ralph DePalma, MD, FACS
  Special Operations Officer, VA Office of Research and Development
  Veterans Health Administration, Washington, DC
- Audrey Kusiak, PhD
  Scientific Program Manager, VA Office of Research and Development
  Veterans Health Administration, Washington, DC
- David Cifu, MD
  Senior TBI Specialist, VA Office of Research and Development
  Veterans Health Administration, Washington, DC

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Friedhelm Sandbrink, MD
  George Washington University & VA Central Office
  Washington, DC
- Joel Scholten, MD
  Georgetown University & VA Central Office
  Washington, DC
- Linda Picon, MCD, CCC-SLP
  VA Central Office
  Washington, DC
- Lisa Brenner, PhD, ABPP
  VA Eastern Colorado Health Care System
  Aurora, CO
- Mary Jo Pugh, PhD, RN
  The University of Utah School of Medicine & Salt Lake City VA Health Care System
  Salt Lake City, UT
- Erin Krebs, MD, MPH
  University of Minnesota & Minneapolis VA Health Care System
  Minneapolis, MN
- Robert Kerns, PhD
  Yale University
  New Haven, CT
- Jason Sico, MD, MHS
  Yale School of Medicine & VA Connecticut Healthcare System
  New Haven, CT

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.