# DISCUSSION

We identified 27 studies reporting chronic pain prevalence estimates in Veterans and SMs with a history of mTBI, 1 study that reported on prevalence of suicide-related behaviors among Veterans diagnosed with mTBI and chronic pain versus those with mTBI but no chronic pain diagnoses (and those with no mTBI), and 3 studies examining interventions for the treatment of chronic pain in Veterans and SMs with a history of mTBI. Included prevalence studies describe a wide range of chronic pain types, with the most common being head pain (23 studies), followed by back pain (10 studies), and arm, leg, and/or joint pain (9 studies). Four studies reported data on the use of pain medications (eg, analgesics including opioids, non-opioid analgesics) among Veterans and SMs with mTBI, which we abstracted as a proxy measure for chronic pain (see Figure 8). Across studies addressing KQ1 and KQ2, there was significant heterogeneity in sample sizes (ie, 40 to 102,055 Veterans or SMs with history of mTBI), target populations (eg, Veterans, SMs, or both; era of service; combat exposure history; geographic region; comorbid physical or mental health conditions; and healthcare use), time since mTBI, and length of follow-up, as well as the methods used to identify, define, and operationalize both mTBI and chronic pain. In the studies addressing KQ3, all 3 interventions targeted the treatment of chronic headaches following mTBI – none examined other pain locations or compared efficacy of chronic pain treatments between those with and without mTBI history.

Figure 8 Number of studies reporting prevalence of chronic pain in Veterans and Servicemembers with mTBI by pain type

Note. Some studies reported multiple pain types.

Across these studies, the prevalence of chronic pain among Veterans and SMs varied widely but, overall, was high. In studies providing comparisons, pain prevalence estimates were consistently higher among those with, versus without, mTBI history, and for those with comorbid mTBI and PTSD compared to those with mTBI but no PTSD. While more recent literature distinguishes between chronic pain and “high impact chronic pain,”^62^ the studies meeting our inclusion criteria were generally published prior to when this distinction was more commonly used, and therefore type and impact of chronic pain were often unclear. As expected in this population, prevalence estimates of head pain and those of chronic pain generally were higher than estimates of other specific chronic pain conditions (eg, chest pain, abdominal/stomach pain). However, across studies, there were wide ranges of prevalence estimates for each pain type, likely due to the varying study designs, target populations or samples, pain definitions, operationalization of key variables, and pain ascertainment periods (see Figure 9). This heterogeneity across studies limits the conclusions that can be drawn about the frequency of pain or the most common pain types among Veterans and SMs who experience mTBI.

Figure 9 Range of chronic pain prevalence estimates by pain type across studies

For general chronic pain among Veterans with a history of mTBI, a relatively robust prevalence estimate of 59% was identified in a large study of Post-9/11 Veterans who use VA healthcare and completed the Comprehensive TBI Evaluation (CTBIE).^4^ This estimate was derived from a population-level database and, thus, represents a relatively large target population. However, Veterans who complete the CTBIE are generally seeking treatment for a variety of post-deployment health symptoms that may or may not be related to mTBI, or pain. The CTBIE is a standardized and templated clinical assessment completed by a specialty provider and includes standardized assessments of pain; however, patients who complete the CTBIE may not need pain-related care (ie, are not bothered by pain). When CTBIE data or pain diagnosis codes are used to estimate chronic pain, as in the case of this study, the true prevalence of chronic pain may be over- or underestimated.^3,5^ Most other studies examining general chronic pain included fewer than 500 participants, and varied in their methods used to identify and define chronic pain. The only other large study utilized EHR data and reported prevalence estimates of 82% for Veterans with a history of mTBI and comorbid PTSD, and 71% with no PTSD.^39^ This study identified chronic pain by the presence of a single pain-related ICD diagnosis code, and may over- (or under-) estimate pain prevalence due to this approach.^3,5^ Studies of pain disability/interference (defined as moderate-to-severe interference in daily functioning) due to chronic pain provided relatively consistent estimates of 70–75%.^4,44^ Studies of pain severity, based on self-report using Likert-like scales, indicated that roughly half of Veterans and SMs with a history of mTBI reported moderate to extreme/very severe pain,^41,53^ and studies that examined pain frequency reported that about one-third to one-half of SMs and Veterans with a history of mTBI experience pain more than 15 days per month.^42,46,50,54^

Head pain such as headaches and migraines were the most-studied chronic pain type among Veterans and SMs with mTBI history; prevalence estimates varied widely from 3% to 98%. Relatively robust, but still widely varied, estimates were derived from 5 large studies, all of which used her or CTBIE data and thus, for the reasons indicated above, may not represent the true prevalence of head pain across the population of Veterans or SMs with mTBI history.^7,39,45,52,53^ Prevalence estimates of headache or migraines from 4 studies of Post-9/11 Veterans with a history of mTBI ranged from 20% to 94% (this latter study reported data from a CTBIE item assessing the presence of any headaches), and 1 study of SMs reported a prevalence of 15%. Prevalence estimates appear to vary substantially by target population (eg, Veteran versus Servicemember; healthcare utilization), time since mTBI, length of follow-up, method for identifying and classifying chronic pain (and possibly mTBI), and data source.

Prevalence estimates for back pain were largely consistent, falling between 32% and 44% for SMs in 3 studies using the PHQ-15,^15,59,60^ and 13%-15% for upper back pain, and 53%-58% for lower back pain among Veterans who completed the CTBIE.^52,53^ The 3 studies that used the PHQ-15^15,59,60^ also used similar methods overall, including a focus on very similar SM populations. We were unable to determine whether there was overlap between individual participants in these studies – a possibility given the database utilized. Therefore, we retained all 3 studies and report findings for all pain measures presented (which were remarkably consistent across studies).

There was wide variation in the prevalence estimate of neck pain in Veterans with a history of mTBI. The 2 largest studies reported prevalence estimates of 6% (VA EHR data) and 23% (CTBIE).^7,40^ With the exception of arthritis (41% to 44%),^40,57^ the prevalence levels of other pain types were relatively low.

Four articles reported data on pain medication use, which we abstracted as a proxy measure for chronic pain. Of these, 2 relatively small studies^40,42^ specifically looked at opioid use. Estimates were disparate at 12% and 49% of Veterans with a history of mTBI, but these studies differed substantially in data source, population, and timing of follow-up. None of these studies measured the chronicity of opioid or other pain medication use; as such, it was unclear if these medications were used for chronic pain or for more intermittent pain. Future studies that examine the prescription of pain medications to Veterans and SMs with mTBI should specify the duration of medication use.

Three studies compared the prevalence of chronic pain in Veterans and SMs with a history of mTBI by etiology of the mTBI (all 3 compared blast versus non-blast etiologies). None of these studies provided compelling evidence that prevalence differed by etiology. However, 1 study presented data on headache prevalence among Veterans who experienced LOC after their mTBI, versus those who only experienced AOC, and by blast versus non-blast etiology. This study reported a statistically significant difference in headache prevalence among those whose mTBI resulted in LOC and was associated with blasts versus those whose mTBI resulted in LOC but was not associated with blasts (40% versus 23%, respectively).^60^ There were no differences by blast/non-blast etiologies among those whose mTBI resulted only in AOC. None of the other pain types assessed in this study differed by mTBI etiology. Notably, none of the studies examined or compared pain prevalence by location of mTBI, location of co-occurring injuries, or timing of pain onset relative to the mTBI, which may all have important implications for onset and chronicity of pain conditions.

Although we did not find strong evidence suggesting that pain prevalence varied by mTBI etiology, it was clear across studies that, when examined, pain prevalence levels were substantially higher among those with comorbid PTSD. Although the assessment of pain prevalence by comorbid PTSD was not a specified focus of KQ1, the consistency of this finding across studies is noteworthy, particularly given the high prevalence of diagnosed PTSD among those with a history of mTBI. This finding lends further evidence to prior discourse about the “polytrauma clinical triad”^25^ and has implications for the ongoing clinical management of Veterans and SMs with mTBI. Notably, we did not find parallel comparisons in pain prevalence by other mental health comorbidities. This is an evident gap in the literature as other mental and behavioral health conditions are also highly prevalent among those with mTBI (eg, depression, substance use disorders) and it is likely that pain conditions may also vary by the presence of these comorbidities. Such data may also have clinical implications for treatment of pain conditions among those with mTBI history. Importantly, Veterans with mTBI have considerably higher VA healthcare utilization and care costs than those without mTBI history, a large proportion of which is associated with pain and mental health care utilization.^63,64^ Research that helps forecast ongoing healthcare needs and that, ultimately, can lead to improved functioning and quality of life outcomes for this complex patient population is critical.

In contrast to large differences between those with and without comorbid PTSD, the studies that reported pain prevalence by “severity” of mTBI (ie, mTBI events associated with LOC versus those only associated with AOC) reported only small differences, with slightly higher pain prevalence among those who experienced more severe mTBI.^15,44,46,49,59,60^ However, slightly larger differences in prevalence by mTBI severity were observed in the studies examining head pain.^15,59,60^

As evident, there was relatively little consistency in the design or outcomes of the studies used to address KQ1 and KQ2. Although the wide variation in estimates is not surprising given the heterogeneity in methods across studies, these findings, or rather the lack of concrete findings, highlight a need to establish and implement consistent methods to assess pain conditions that are prevalent in US Veteran and SM populations. Studies are needed to assess the prevalence of chronic pain among all US Veterans and SMs with a history of mTBI (rather than, for example, treatment-seeking Veterans specifically) and to compare the prevalence levels of pain types by important Veteran and SM characteristics, including service history, physical and mental health comorbidities, and healthcare utilization patterns. Additionally, despite being beyond the scope of this review, we noted that few studies compared pain prevalence between those with and without mTBI and, thus, it remains unclear how pain conditions are associated with mTBI (ie, whether they tend to be more commonly diagnosed among treatment-seeking samples, whether they are a result of the mTBI itself, or whether they are a result of the same characteristics and exposures that led to mTBI). To answer these questions and to maximize usefulness of the evidence, studies that randomly sample Veterans and SMs, follow them over time, and use established and consistent definitions and operationalizations of mTBI and pain are needed.

Similarly, although we found well-conducted studies of treatment-seeking samples of Veterans and SMs that reported on chronic pain among those with mTBI, these studies by nature relied on selective (ie, non-random) samples and/or proxy measures of mTBI and pain such as ICD diagnosis codes. In some studies, ICD diagnoses were used to identify potential pain conditions even if the specific diagnoses are not associated with pain in all cases. For example, osteoarthritis diagnoses are used as a proxy for chronic pain in some studies, but recent research suggests that individuals diagnosed with osteoarthritis are not necessarily experiencing chronic pain.^65^ To better understand the prevalence of chronic pain conditions and, in particular, to anticipate treatment needs among Veterans and SMs who utilize the VA or Military Health System, random or otherwise representative samples of individuals with (and, for comparison, without) mTBI should be assessed using established and consistent chronic pain definitions and measures.

It is notable that a large number of studies focusing on chronic pain among Veterans with a history of mTBI were excluded from this review because they did not report prevalence levels but, rather, outcomes of pain measures on a continuous scale (ie, means and medians). This precluded our ability to synthesize these studies in the current review, but it stands to reason that additional information on pain severity, frequency, and interference, as well as differences in these measures by pain etiology or assessment methods, may be gleaned from this body of literature. Our review used a relatively flexible definition of “chronic pain” so as not to exclude potentially useful data. Although this approach increased the variance across studies in terms of pain outcomes, we felt this was an acceptable trade-off in attempt to include as many published studies as possible. As described above, our review did not examine the potential impacts of comorbid mental health conditions on prevalence estimates or outcomes of chronic pain, and this limitation could be addressed in future systematic reviews of this body of literature.

A secondary purpose of this review was to describe strategies researchers use to assess chronic pain as part of clinical trials. While all 3 intervention studies used the BPI – a common and well-validated measure of pain intensity and function – the small number of studies examining interventions for chronic pain in this population precludes most generalizations about measures used to assess pain. Future trials should rely on validated, commonly used measures to facilitate comparisons across studies. The Initiative on Methods, Measurement, and Pain Assessment in Clinical Trials (IMMPACT) has developed recommended measures and outcomes that should be assessed in chronic pain clinical trials, including the domains of pain intensity, physical functioning, emotional functioning, improvement and satisfaction with treatment, adverse events, and treatment adherence.^66,67^ These recommendations were promoted by a recent VA workgroup on developing core outcome measures in chronic pain research, which also recommended including changes in sleep as a study outcome.^68^ Future chronic pain research in Veterans and SMs with mTBI history would benefit from the continued use of these strategies for assessing pain and its associated consequences.

Results for KQ1c examining pain assessment methods suggest that different types of pain assessment methods were associated with higher or lower pain prevalence estimates. In addition to pain assessment methods, other aspects of study design likely influenced prevalence estimates. For example, studies of specialized clinics designed to treat a particular condition would be expected to have higher rates of that condition (such as in the study by Ruff et al,^6^ of a small sample seen in a polytrauma clinic) than studies examining the prevalence in a broad, full, or “all-comers” population (such as in studies examining all post-deployment SMs or identifying pain diagnoses in the EHR).

For this review, we included studies of chronic pain even if the study did not include a rigorous assessment to determine the chronicity or severity of symptoms. For example, we included studies where pain symptoms were assessed only for the past month. While this methodology could result in over-estimation of the prevalence of chronic pain, we opted to include these studies in order to generate a fuller picture of the problem of pain among patients with a history of mTBI. Future research that aims to understand chronic pain in a sample of all Veterans/SMs with mTBI history, or of specified treatment-seeking Veterans/SMs with mTBI history, would benefit from the assessment of pain chronicity (at least 3–6 months) and severity (moderate or higher). There are also recommended strategies for assessing chronic pain using administrative data, such as ICD diagnosis codes, that can improve the accuracy and comparability of prevalence estimates in these types of studies of chronic pain.^3^

We found only a single study examining suicide-related outcomes in US Veterans and SMs with both chronic pain and a history of mTBI.^7^ This study used VA EHR data and categorized Veterans with and without a history of mTBI into trajectory groups based on an algorithm using ICD diagnosis codes. As compared to those with relatively low rates of mental health, pain, and other sensory diagnoses during the trajectory development period, Veterans with high mental health, post-concussive symptoms, and pain comorbidities were significantly more likely to have been diagnosed with suicidal ideation or attempt during the follow-up period. This study compared the prevalence of suicide-related behaviors between those with and without a history of mTBI (eg, 6.6% versus 2.4%, respectively) but did not likewise directly compare suicide-related behaviors between those with mTBI with and without comorbid pain. However, considering the persistently higher rates of suicide in Veteran populations, and evidence suggesting increased risk among Veterans with mTBI,^10,11,29,30^ more research of this particularly vulnerable population is urgently needed.^8,9^

Although chronic pain is well established as a common comorbidity among Veterans and SMs with a history of mTBI, we found very few trials of interventions to treat chronic pain in this population, even when searching for studies from any country. The 3 studies that met inclusion criteria were small and provide insufficient strength evidence supporting the interventions studied (rTMS in 2 RCTs and FNS, a type of neurotherapy, in 1 small pre-post trial).^12-14^ All 3 studies targeted chronic headaches, and none assessed nor treated other types of chronic pain. Also of note is that no studies compared the efficacy of chronic pain treatments among those with, versus without, mTBI. This review was limited to chronic pain treatment trials of Veterans and SMs from any country with a history of mTBI because of the unique military-related circumstances (eg, blast exposure) that can contribute to pain in this population. However, due to the very small number of trials specific to this population, future efforts should consider results from pain interventions among broader populations (eg, adult civilians) or Veterans and SMs without a history of mTBI when making treatment, policy, or research scoping decisions. Future research could compare responses to chronic pain interventions for participants with and without mTBI history to determine mTBI results in a greater or lesser likelihood of benefit. Without such information, screening for presence and intensity of pain are likely warranted for Veterans and SMs with a history of mTBI so that they can be offered evidence-based treatment for chronic pain if needed.

Due to the prevalence of mTBI, and the prevalence and debilitating nature of chronic pain, in the population of Veterans and SMs, it is clear that more research targeting the treatment of chronic pain amongst those with mTBI history is warranted. Specifically, studies of interventions established to be effective for treating chronic pain in other patient populations, particularly

Veterans and SMs without mTBI, should be prioritized for testing in those with mTBI history. Additionally, because rTMS has been studied in 2 small, pilot RCTs with a strong sham comparator and has shown positive preliminary findings,^12,13^ additional, larger RCTs of rTMS for chronic pain in Veterans and SMs with mTBI history are likely warranted.

## CONCLUSION

Chronic pain, particularly head and back pain, is common among US Veterans and Servicemembers with a history of mTBI, as is the use of pain-related medications, including opioids. Although pain is prevalent among Veterans and SMs in general, the results of this review suggest that those with mTBI history – and especially those with comorbid mTBI and PTSD – experience pain at higher prevalence levels than those without a history of mTBI. Based on the existing research, precise estimates of the prevalence of pain conditions, locations, disability/interference, and severity are hampered by heterogeneity in study populations/samples, timing of pain ascertainment relative to individuals’ mTBI history, duration of study follow-up, and methods used to identify, define, and operationalize both mTBI and chronic pain. Additionally, only a single study examined the risk of suicide, and only 3 studies tested interventions to mitigate pain in this complex population. Thus, the prevalence of chronic pain in the general population of US Veterans and SMs, the impact of comorbid pain and mTBI on suicide risk in this potentially high-risk population, and the efficacy of pain therapies among those with comorbid mTBI and chronic pain remain largely unknown. Research studies, specifically designed with the intent of filling these knowledge gaps, are needed to inform current and future service needs for this population. Given the high prevalence of mTBI in Veterans and Servicemembers, and the importance of meeting the social and clinical needs of this large population, this research is urgent and essential.