# RESULTS

We reviewed a total of 2,081 studies. After title and abstract review, 174 met inclusion criteria. Upon full-text review, we included a total of 27 prevalence studies, 2 RCTs, and 1 pre-post study (see Figure 2).

Figure 2 Literature Flow Chart

*after deduplication. KQ = Key Question

†See Appendix D for full list of excluded publications.

Note: KQ2 study is also included in KQ1.

## KEY QUESTION 1 What is the prevalence of chronic pain in US Veterans or Servicemembers with a history of mTBI?

### Summary of Findings

We found 27 articles that reported chronic pain prevalence estimates for Veterans and/or Servicemembers (SMs) with a history of mTBI. General chronic pain prevalence was reported in 8 studies,^4,25,39-44^ and head pain (eg, headaches and/or migraines) in 23 studies.^6,7,15,39,40,42,44-60^ Other types of chronic pain for which prevalence estimates were reported included: back pain (10 studies^7,15,40,44,49,52,53,56,59,60^); neck pain (5 studies^7,40,44,52,53^); arm, leg, and/or joint pain (9 studies^15,39,42,49,52,53,56,59,60^); abdominal/stomach pain (5 studies^15,40,56,59,60^); chest pain (3 studies^15,59,60^); sexual pain/problems (3 studies^15,59,60^), prescription pain medication use (4 studies^40-42,54,61^), arthritis (2 studies^40,57^); and other pain (4 studies^7,39,40,42^). Three articles included data from the 4-site VA/Department of Defense (DoD) Chronic Effects of Neurotrauma Consortium (CENC) longitudinal study,^41,57,61^ albeit with different subsets of the total sample, and therefore we only included data that was not duplicative from those articles – taking the prevalence estimate with the largest denominator when more than 1 estimate for the same measure was available. Sample sizes ranged from 40^47^ to 102,055^45^ Veterans or SMs with history of mTBI. Studies also varied widely in target population (eg, SMs or Veterans, geographic region, era served, comorbidities) and definitions and measures used to classify mTBI and chronic pain. Characteristics of the studies are in Table 2. Prevalence estimates from these studies are provided in Tables 3 through 5.

Table 2 Characteristics of studies reporting prevalence of chronic pain in Veterans/Servicemembers with a history of mTBI

Author, Year N total pts*; Setting Dates; Study Design Data Collection | mTBI; N pts with history of mTBI; mTBI assessment and definition | Eligibility; study inclusion/exclusion criteria | Demographics; Age: mean (SD); Female: %; Race: %; SMs or Veterans; Mental health comorbidities, mTBI injury details (mechanism, # of mTBIs) | Type(s) of CP assessed
Author, Year N total pts*; Setting Dates; Study Design Data Collection | mTBI; N pts with history of mTBI; mTBI assessment and definition | Eligibility; study inclusion/exclusion criteria | Demographics; Age: mean (SD); Female: %; Race: %; SMs or Veterans; Mental health comorbidities, mTBI injury details (mechanism, # of mTBIs) | General | Head | Back | Neak | Arm/leg/joint | Stomach/abdominal | Chest | Sexual | Pain medication use | Arthritis | Other
Beswick-Escanlar, 2016^45^; N=222,036; Multi-site: Military Health System 2006–2015 Cohort – retrospective. | N=102,055; EHR (based on incident ICD diagnosis codes) between 2006 and 2014, with 1-year follow-up period (2006–2015). | Active component Army, Navy, Air Force, and Marine Corps SMs with no prior history of medical care for TBI, headache, or migraine documented in EHR. | Age: 55.2%<24 yrs; 33.3% 25–24 yrs; 9.8% 35–44 yrs; 1.6% 45–54 yrs; 0.1% 55+ yrs.; Female: 8.1%.; Race: 76.4% White; 12.1%; African-American/Black; 11.5% other.; 100% SMs.; PTSD: 22.2%. | | X
Brickell, 2014^42^; N=167; 1 site: WRAMC Dates NR Cohort – prospective. | N=167; Routine comprehensive clinical evaluation by healthcare professional; mTBI=PTA<24 hrs and LOC>15 mins (could have intracranial abnormality). | SMs with mTBI and polytrauma sustained during deployment (combat or other) who had undergone a TBI clinical evaluation within the first 3 months of injury and participated in ≥1 follow-up telephone interview. | Age: 27.6 (7.0) yrs.; Female: 3.6%.; 100% SM.; Blast: 74.3%.; Wounded OIF: 79.6%.; Wounded OEF: 13.2%.; Wounded Other: 7.2%. | X | X | | | X | | | X | | X
Couch, 2016^46^; N=110; 1 Site: Oklahoma City VA outpatient clinic designed to assist Veterans in return to civilian life. 7/2012 - 8/2014. Case-control. | N=55; mTBI with LOC: n=23; mTBI with AOC: n=20; VA/DoD common definition, based on TBI screen followed by TBI clinic evaluation. | Male post-deployment, Post-9/11 Veterans that participated in this specialty clinic. All were age 20–60, confirmed to have deployment-related TBI (cases), and 4–11 years post-TBI. | LOC: Age: 20–29=35%; 30–39=39%, ≥40=26.2%.; AOC: Age: 20–29=35%; 30–39=40%; ≥40=25%.; Female: 0%.; Race NR.; 100% Veterans. | | X
Farrell-Carnahan, 2015^47^; N=112; 4 sites: VA Polytrauma Rehabilitation Centers (PRC). Jan 2009–Mar 2013.; Cross-sectional. | N=40; VA/DoD common definition, based on VA PRC TBI Model System Form 1 inpatient data collection at time of study enrollment. | Veterans 18+ yrs receiving care for TBI and/or TBI-related issues in VA inpatient rehabilitation program and enrolled in VA PRC TBI Model System within 1-year of injury. Also required TBI severity information and at least partial completion of a 1-year follow-up assessment (including NSI and/or patient proxy). | Age: 29 (13) yrs.; Female: 7%.; Race: 70% White.; 100% Veteran.; Cause of injury: motor-vehicle related 10/40 (25%); other violence (blast) 21/40 (53%); all other 9/40 (23%). Injured during deployment: 26/40 (65%). | | X
Hoge, 2008^15^; N=2,525; Single-site: Walter Reed Army Institute of Research. 2006.; Cross-sectional. | N=384 (LOC=124; AOC=260); Screening questionnaire consistent with VA/DoD common definition. | SMs (active or reserve US Army combat infantry brigade) 3–4 months after return from combat deployment to Iraq. Exclusions: missing data from injury questions or reported having had a head injury without LOC or AOC. | LOC vs AOC:; Female: 1/123 (0.8%) vs 3/258 (1.2%).; Age<30 yrs: 79/123 (64.2%) vs 149/257 (58.0%).; 100% SMs.; PTSD: 54 (43.9%) vs 71 (27.3%).; Major depression: 27 (22.9%) vs 21 (6.6%). Mechanism of injury: Blast or explosion 98 (79.0%) vs 189 (72.7%); Bullet 6 (4.8%) vs 2 (0.8%); Fragment or shrapnel 31 (25.0%) vs 48 (18.5%); Fall 38 (30.6%) vs 73 (28.1%); Vehicle accident 38 (30.6%) vs 47 (18.1%); Other 16 (12.9%) vs 23 (8.8%). | X | X | | X | X | X | X
Hoot, 2018^41^; N=454; 4 sites: VAMCs in Richmond, VA; Tampa, FL; San Antonio, TX; and Houston, TX. 2016–2017.; CENC.; Cross-sectional. | N=379; DoD/VA common definition. Each potential concussive event identified was investigated via the VCU rCDI. | Post-9/11 Veterans/SMs with combat exposure. Exclusion: (1) history of moderate or severe TBI; (2)history of major neurologic or psychiatric disorder. | Median age: 36.0 (range 22–64).; Female: 11.6%.; Race: 67.3% White; 22.7% African-American/Black; 10.0% other.; Ethnicity: 23.6%; Hispanic/Latino.; PTSD (MINI): 31.2%.; Depression (PHQ-9): 43.1%. | X | | | | | | | X
Jackson, 2016^48^; N=1,312; Numerous: Nationally dispersed Veterans enrolled in Project VALOR 2009–2012 Cohort – retrospective. | N=612; VA/DoD common definition, based on VA 4-item TBI screen plus clinical interview by doctoral-level clinician. | Post-9/11 reserve or active duty (Army and Marine) Veterans with history of mTBI (with or without LOC) required to have undergone a mental health evaluation at a VA facility, indicated by a diagnostic interview or psychotherapy procedure code July 2008-Dec 2009. Must not have been participating in a clinical trial at the time of enrollment or have moderate/severe TBI, or TBI of unknown severity. Individuals with probable PTSD were oversampled at a 3:1 ratio; females were oversampled at a 1:1 ratio. | Age: 37.1 (9.8) yrs.; Female: 52.8% female.; Race/Ethnicity: 66.5% White; 15.6% African American/Black; 13% other.; 100% Veterans.; Major depression: 38.5%.; Current PTSD: 51.9%.; PTSD + Depression: 30.9%. | | X
King, 2014^40^; N=842; Multi-site: VA Integrated Service Network 2 (upstate NY + parts of northern PA). Oct 2001-Sept 2011.; Cross-sectional. | N=421; ≥1 encounter with ICD code 310.2 (post-concussion syndrome). | Post-9/11 Veterans who used VA primary care. | Age: 30.3 (7.6) yrs.; Female: 4%.; 100% Veterans. | X | X | X | X | | X | | | X | X | X
Kulas, 2018^39^; N=164,884; Muti-site: National data (VA EHR) 10/1/2011 - 9/30/2012.; Cohort – retrospective. | N=32,316 (23,063 mTBI+PTSD; 9,253 mTBI no PTSD); EHR (based on ICD diagnosis codes) during fiscal year 2012. | All Post-9/11 Veterans who received care in VHA and had ≥1 ICD diagnosis code for mTBI. | mTBI + PTSD group:; Age: 32.8 (8.3) yrs.; Female: 5%.; mTBI no PTSD group:; Age: 32.1 (8.6) yrs.; Female: 8%. | X | X | | | X | | | | | | X
Lew, 2009^25^; N=340; Single-site: VA level 2 polytrauma clinic. Jan 1, 2007 - Oct 27, 2008 (22 months).; Cross-sectional. | N=227; Clinical determination of mTBI on CTBIE based on VA/DoD common definition. | All Post-9/11 Veterans with persistent postconcussive symptoms seen at the polytrauma clinic. | NR | X
MacGregor, 2013^49^; N=992; Multi-site: Navy/Marine deployment health database. Mar 2004 – Apr 2008.; Cohort – retrospective. | N=334; EHR: ICD diagnosis codes indicative of TBI with corresponding Abbreviated Injury Score values of 1 or 2. | Iraq War SMs (Navy/Marines) who sustained minor to moderate injuries and completed a PDHRA after deployment (within 1 year of injury). | Age: 23.3 yrs (range 18–45).; Female: 0.3%.; Race: NR.; Mechanism of injury:; Battle, blast: 297 (88.9%).; Battle, nonblast: 8 (2.4%).; Nonbattle: 29 (8.7%). | | X | X | | X
Patil, 2011^50^; N=246; Single-site: large, midwestern polytrauma network site. June 15, 2007 - July 15, 2009.; Cohort – retrospective. | N=246 (56 evaluated in Neurology); VA/DoD common definition, based on VA CTBIE. | Post-9/11 combat Veterans receiving care at a VA polytrauma network site with combat-related mTBI. | Age: 27.9 (6.3) yrs.; Female: 7.7%.; Race: 85.8% White.; Ethnicity: 19.1% Hispanic.; Mechanism of injury:; 1+ blast exposure: 65%. | | X
Powell, 2015^43^; N=171; Single-site: Boston VA TRACTS Center of Excellence.; Cross-sectional. | N=171; Clinical interview by doctoral-level psychologist (reviewed by 3+ doctoral-level psychologists for consensus diagnosis). | Post-9/11 Veterans. Excluded: (a) a history of seizures; (b) prior serious medical illness; (c)current active suicidal and/or homicidal ideation, intent, or plan requiring crisis intervention; (d) DSMIV-TR diagnosis of current bipolar disorder, schizophrenia, or other psychotic disorder (except psychosis not otherwise specified [NOS] due to trauma-related hallucinations); or (e) cognitive disorder due to general medical condition other than TBI. Participants with any history of moderate to severe TBI were excluded. | Age: 33.3 (8.6) yrs.; Female: 13.5%.; Race/Ethnicity: Black/African-American; 10.5%; Hispanic/Latino 17%; White 68.4%.; Current mood disorder: 30.4%.; Current anxiety disorder: 22.2%. | X
Pugh, 2019^7^; N=527,381; Multi-site: VA EHR data. Oct 1, 2001 - September 30, 2011.; Cross-sectional. | N=93,003; VA/DoD common definition, based on comprehensive algorithm using DoD trauma data, VA CTBIE data, and ICD diagnosis codes. | Veterans who met criteria for mTBI. Included: (a) entered VA care Oct 1, 2001-September 30, 2011; (b) received ≥5 years of VA care (inpatient, outpatient, or pharmacy) before Sept 30, 2014; and (c) received ≥1 year of care after 2007. | Age: 29.8 (7.8) yrs.; Female: 6.0%.; Race/Ethnicity: White 69.6%; Black/African American 13.3 %; Hispanic 12.6%; Asian 2.1%; Native American/Pacific Islander 1.7%.; 100% Veteran. | | X | X | X | | | | | | | X
Romesser, 2012^44^; N=433; 2 sites: VAMC polytrauma clinics.; Cohort – retrospective. | N=354; Clinical interview: Self-reported history of mTBI based on VA/DoD common definition and identifying a mechanism of injury. | Post-9/11 Veterans with mTBI referred to VA polytrauma clinic. Excluded: Incomplete demographic and/or injury severity characteristics, missing pain or headache data, or with ≥2 items missing on PTSD Checklist. | Age: 31.0 (8.2) yrs.; Female: 4.6%.; Race/Ethnicity: Black/African-American 15%; White 63.7%; Hispanic 17.3%; other 3.9%. | X | X | X | X
Ruff, 2008^6^; N=126; Single-site: Cleveland, OH VA polytrauma network site.; Dates NR.; Cross-sectional. | N=126; VA/DoD common definition, based on VA CTBIE. | Post-9/11 combat Veterans receiving care at a VA polytrauma network site with deployment- and blast-related mTBI. | Demographics NR.; 100% Veteran. | | X
Schwab, 2017^51^; N=1,567; 2 sites: Fort Carson, CO, and Fort Bragg, NC.; Cohort – prospective. | N=557 at baseline; 358 with mTBI completed 3-month follow-up.; VA/DoD common definition, based on screening followed by OSU TBI-ID interview. | Post-9/11 Army SMs recently returned from Iraq/Afghanistan with positive TBI screen. Excluded: having been medically evacuated from theater, determined that likely incurred more than a mild TBI, and likely symptom exageration. | Age: 27 (6) yrs.; Female: 8%.; Race/ethnicity: 65.8% White; 13.6% Hispanic; 11.2% African American/Black; 9.4% multiple.; Experienced blast: 67%.; PTSD screen: 15% positive. | | X
Seal, 2017^4^; N=116,913; Multi-site: VA CTBIE database. October 2007-March 2015.; Cohort – retrospective. | N=65,675; Clinical determination of mTBI on CTBIE based on VA/DoD common definition. | Post-9/11 Veterans with determinate TBI finding on CTBIE, VA EHR data during year before or after CTBIE, sufficient CTBIE data to classify TBI severity, complete data. | Age: mean NR.; Female: 6.1%.; Race: 39.9% Other-than-white.; 100% Veteran.; PTSD: 65.8%.; Depression: 39.4%.; Alcohol Use Disorder: 15.9%.; Drug Use Disorder: 8.7%. | X
Suri, 2019^52^; N=36,880; Multi-site: VA CTBIE database 7/1/2009 - 9/30/2013.; Cohort – prospective. | N=23,703; VA/DoD common definition, based on CTBIE. | Post-9/11 Veterans aged 18–65 years who had: (1) complete data for the presence and/or duration of the most severe episodes of deployment-related LOC, PTA, and/or AOC experienced; (2) complete data for the CTBIE clinician’s overall assessment of deployment-related TBI history (Y/N); (3) agreement between #1 and #2; and (4) no self-reported occurrences of pre-deployment or post-deployment TBI. | Age: 33.3 (7.7) yrs.; Female: 5.1%.; Race: Asian 2.0%; Black/African-American 13.2%; Hawaiian/Pacific Islander 1.5%; American Indian/Alaska Native 1.3%; White/caucasian 69.7%; Unknown/NR 12.4%.; Depression: 37.0%.; PTSD: 67.7%.; Alcohol abuse/dependence: 7.2%.; Drug abuse/dependence: 2.4%.; Non-blast TBI only: 21.8%.; Blast TBI only: 46.6%.; Blast+non-blast TBI: 31.6%. | | X | X | X | X
Suri, 2017^53^; N=2,187; 24 VA facilities nationwide: CTBIE database. 7/1/2009–9/30/2013.; Cohort – prospective survey ~3 yrs after CTBIE). | N=1,683; VA/DoD common definition, based on CTBIE. | 18–65 years; Agreement between clinician TBI impression and expected diagnosis based on VA/DoD criteria for AOC, LOC, and PTA; Past TBI history limited to nondeployment-related TBIs only. | Age: 36.6 (9.2) yrs.; Female: 8.7%.; Race: NR.; 100% Veteran.; Depression: 29.8%.; PTSD: 48.6%.; Alcohol abuse: 4.8%.; Drug abuse: 1.6%.; Non-blast TBI only: 25.8%.; Blast TBI only: 56.4%.; Both blast/non-blast TBI: 17.8%. | | X | X | X | X
Theeler, 2012^54^; N=978; Single-site: Madigan Army Medical Center.; Cross-sectional. | N=978; Screening: Initial 2-question screen followed by 10-question screen (scored in a standardized manner from 0 to 39); concussion=score of ≥5 on the 2-plus-10 questionnaire. SMs with positive screen then evaluated in TBI clinic. | SMs who had a deployment-related concussion in Iraq or Afghanistan. | NR | | X | | | | | | X
Tsao, 2017^55^; N=2,612; 3 sites: Camp Lejeune, NC; Twentynine Palms, CA; and Kaneohe Bay, HI. 4/2010 - 6/2013.; Cross-sectional. | N=2,612; VA/DoD common definition, based on screening questions. | Male SMs (Marines) were 2–8 weeks post-deployment in Iraq and/or Afghanistan and saw greatest amount of combat but did not sustain injury requiring medical evacuation and were not on restricted duty. | Median age: 22 years (range 19–50); 95% were<33 years; 99% were<39 years; Female: 0%; 100% SMs | | X
Vanderploeg, 2009^56^; N=4,462; Randomly-sampled US Veterans flown to VAMC and University of South Florida, Tampa, FL. Mid-1980s.; Cross-sectional. | N=278; Those who had a head injury with AOC. Interview: (1) Since your discharge from active duty, have you injured your head? and (2) Did you lose consciousness as a result of the head injury? (If participants were unclear if they had lost consciousness, they were asked if they had “blacked out” in the accident.). | Male, Vietnam-era, Army Veterans who had: (1) first entered the military between Jan 1965-Dec 1971; (2) been on active duty for ≥4 months; (3) served only 1 tour of duty; (4) obtained a military occupational specialty; and (5) achieved a pay grade ≤E-5 (sergeant) on discharge. Exluded: Participants that required hospitalization after their head injury. | Age: 78%<40 yrs.; Race: 16% Other-than-white.; 100% Veteran; Approximately half the sample had served in Vietnam, whereas the other half had served elsewhere (ie, United States, Korea, Germany). | | X | X | | X | X
Walker, 2018a^57^; N=492; 4 sites: VAMCs in Richmond, VA; Tampa, FL; San Antonio, TX; and Houston, TX.; Consented for study (CENC) prior to Sept. 2017.; Cross-sectional. | N=414; VA/DoD common definition. Each potential concussive event identified was investigated via the VCU rCDI. | Post-9/11 Veterans/SMs with combat exposure. Exclusion: (1) history of moderate or severe TBI; (2)history of major neurologic or psychiatric disorder. | Age: 36.0 yrs (31.0, 47.0).; Female: 11.8%.; Race: 66.2% White; 23.4% African-American/Black; 10.4% other.; Ethnicity: 23.4% Hispanic or Latino. | | X | | | | | | | X
Webb, 2015^58^; N=513,893; Multi-site: Military Health System. 2001–2008.; Cohort – retrospective. | N=5,065; EHR (based on ICD diagnosis codes). | Air Force SMs who served on active duty for ≥180 days between Oct 1, 2001 - Sept 30, 2008 with incident cases of mTBI. Excluded: history of mTBI or other head injuries in the 2 years prior to entering the study. | Born before 1965: 6.7%.; 1966–1975: 15.7%.; 1976 and later: 77.6%.; Female: 18%.; Race/ethnicity: 75.1% White; 11.6% African-American/Black; 2.5% Asian/Pacific Islander; 6.5% Hispanic; 0.7% Native American; 3.7% Other/Unknown.; 100% SMs. | | X
Wilk, 2012^59^; N=1,502; Single-site: Walter Reed Army Institute of Research. Nov-Dec 2008.; Cross-sectional. | N=260 (LOC=86; AOC=174); Screening questionnaire consistent with VA/DoD common definition. | SMs (3 Army brigade combat teams from 1 Active Component infantry division) 4–6 months after return from combat deployment to Iraq or Afghanistan who met criteria for mTBI. | 72%<30 yrs.; Female: 9%.; LOC vs AOC: PTSD (PCL-17): 52% vs 29% . Depression (PHQ-9): 23% vs 16%. | | X | X | | X | X | X | X
Wilk, 2010^60^; N=3,952; Single-site: Walter Reed Army Institute of Research. 2006–2007.; Cross-sectional. | N=587 (LOC=201; AOC=373); Screening questionnaire consistent with VA/DoD common definition. | SMs (1 Army National Guard and 2 Active Duty infantry brigades) 3–6 months after return from combat deployment in Iraq who met criteria for mTBI. | 66.9%<30 yrs.; Female: 1.7%.; LOC blast vs non-blast:; AOC blast vs non-blast:; PTSD:; 44.7% vs 38.5%.; 30.0% vs 29.1%.; Major depression:; 21.2% vs 15.8%.; 10.2% vs 16.0%.; Alcohol misuse: 39.0% vs 42.1%.; 28.2% vs 37.4%. | | X | X | | X | X | X | X
| | | Total Studies: | 8 | 23 | 10 | 5 | 9 | 5 | 3 | 3 | 4 | 2 | 3

Abbreviations: AOC=Alteration of consciousness; CA=California; CENC=Chronic Effects of Neurotrauma Consortium; CO=Colorado; DoD=Department of Defense; DVBIC=Defense and Veterans Brain Injury Center; FL=Florida; HI=Hawaii; LOC=Loss of consciousness; MINI=Mini-International Neuropsychiatric Interview; mTBI=Mild Traumatic Brain Injury; NC=North Carolina; NR=Not reported; OH=Ohio; OSU TBI-ID=Ohio State University Traumatic Brain Injury Identification Method; P=P-value; PDHA=Post-Deployment Health Assessment; PDHRA=Post-Deployment Health Re-Assessment; PHQ-9=9-item Patient Health Questionnaire scale; PNS=Polytrauma Network Site; PTS=Posttraumatic Stress; PTSD=Posttraumatic Stress Disorder; SD=Standard Deviation; SM=Servicemember; TBI=Traumatic Brain Injury; TRACTS=Translational Research Center for TBI and Stress Related Disorders; TX=Texas; US=United States; VA=Virginia; or Veterans Affairs; VALOR=Veterans’ After-discharge Longitudinal Registry; VAMC=Veterans Affairs Medical Center; VCUrCDI=Virginia Commonwealth University retrospective Concussion Diagnostic Interview; WRAMC=Walter Reed Army Medical Center

### Detailed Results

#### General Chronic Pain

There were 8 studies that reported prevalence of general (or any) chronic pain among Veterans with mTBI: 3 were retrospective cohort studies based on VA administrative data (ie, EHR data) for Veterans who used VA healthcare,^4,39,40^ 1 was a study of injured SMs evaluated at different time points for approximately 5 years post-injury,^42^ and 4 were VA-based studies that either enrolled Veterans for testing or utilized chart review of patients who had been seen in TBI clinics.^25,41,43,44^ All 8 studies focused on Post-9/11 Veterans.

A relatively robust estimate of the prevalence of general chronic pain among Veterans was identified by Seal et al^4^ in a study of 65,675 Veterans with a confirmed history of mTBI based on the VA’s CTBIE. In this study, the prevalence of chronic pain diagnoses (defined as those with 2 or more International Classification of Diseases [ICD] diagnosis codes for pain, greater than 90 days apart, in the year before or after their CTBIE) was 59%. This compared to 53% among those whose CTBIE did not confirm mTBI history. The strengths of this study are that it is broadly representative of the large population of Veteran VA users who have been diagnosed with mTBI by a specialist clinician using the CTBIE. Additionally, the criteria used to identify pain using ICD codes were relatively stringent compared to other studies that use administrative data. However, Veterans who complete the CTBIE are generally seeking treatment for a variety of post-deployment health symptoms that may or may not be related to mTBI, or pain, and thus symptoms may be overreported. Additionally, the use of ICD diagnosis codes in EHR data to estimate the prevalence of health disorders such as chronic pain may lead to over- (or even under-) estimation due to a variety of reasons.^3,5^ Therefore, pain data from this study and other studies relying on CTBIE or EHR diagnosis data may not represent the true prevalence of chronic pain in the population of Veterans and SMs with mTBI.

The Seal et al study^4^ also captured rates of pain disability, which was examined with a 5-item Likert scale from none to very severe interference in daily functioning and quality of life. Moderate-to-very severe interference qualified as pain disability, and the prevalence of pain interference (defined as moderate-to-severe interference in daily functioning) was 75%.^4^ This pain interference finding was consistent with a smaller study (n=354) of Veterans treated consecutively at 2 VA polytrauma program sites, in which 70% had reported moderate-to-extreme pain interference (defined as functional limitations secondary to pain).^44^

The remaining studies were based on a variety of Veteran samples, measures of mTBI history, and definitions/measures of pain. A study by Kulas and Rosenheck^39^ was similar to the Seal et al study in its use of VA EHR data for a large number of Veterans; however, rather than the CTBIE, this study used ICD diagnosis codes to identify Veterans with mTBI. It also examined comorbid PTSD. In this study, 82% of Veterans with both mTBI and PTSD diagnoses also carried a pain diagnosis, while 71% of those with mTBI but no PTSD had been diagnosed with pain (compared to 62% of those with PTSD only). This was consistent with a study by King et al in which 2 or more ICD diagnosis codes for pain, assigned ≥90 days apart, were identified in 76% of Veterans with mTBI (versus 52% of those without mTBI).^40^ Similar figures were presented in a polytrauma clinic chart review study by Lew et al,^25^ in which 86% of Veterans diagnosed with both mTBI and PTSD had been diagnosed with chronic pain, while 71% of those with mTBI but no PTSD had been diagnosed with chronic pain, and in a longitudinal survey of SMs with mTBI by Brickell et al, in which 67% to 89% of respondents in each wave reported bodily pain.^42^ Powell et al^43^ used cross-sectional data from clinical interviews of 171 Veterans enrolled in the VA Translational Research Center for TBI and Stress Disorders (TRACTS) longitudinal study at 1 VA site. Among Veterans with mTBI as confirmed via clinical interview, 38% met study criteria for chronic pain. Hoot et al^41^ reported the prevalence of chronic pain among 379 Veterans enrolled in the CENC study with confirmed history of mTBI; 59% of Veterans reported moderate, severe, or extreme pain or discomfort based on a validated measure of pain intensity, compared to 65% of Veterans with no TBI history. (Brickell et al also reported pain severity among respondents in a longitudinal study of SMs and identified moderate or greater pain intensity among 37% to 59% of respondents across survey time points.^42^)

Additional detail of these and other studies presenting general chronic pain data can be found in Table 3.

Table 3 Prevalence estimates of general chronic pain from studies of Veterans/Servicemembers with a history of mTBI

Author, year N pts with mTBI Population | Pain assessed by | Pain measurement definition/details of assessment tool | Prevalence Results n (%)
Seal, 2017^4^; n=65,675; Post-9/11 Veterans. | EHR data | Presence: Having ≥2 of the same pain ICD diagnosis code more than 90 days apart, 1 year before or after CTBIE. | 38,591/65,675 (58.8%)
Seal, 2017^4^; n=65,675; Post-9/11 Veterans. | CTBIE | Pain interference presence: Ascertained during the CTBIE and defined as an individual’s appraisal of the degree to which pain interferes with their daily functioning and quality of life. Veterans are prompted to endorse level on a 5-item scale, and responses were dichotomized as moderate-to-extreme versus none-to-mild. | 75%
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Presence: Y/N of ICD diagnosis code for pain in EHR. | mTBI+PTSD: 81.5%; mTBI no PTSD: 70.8%
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Presence: If treated for conditions commonly associated with pain for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | 320/421 (76.0%)
Hoot, 2018^41^; n=379; Post-9/11 Veterans/SMs.; CENC sample. | EQ-5D-5L | Intensity: Level of pain or discomfort. [Note that we considered “No or slight pain or discomfort” = no chronic pain, while “Moderate, Severe, or Extreme pain or discomfort” = chronic pain.] | Moderate: 166/378 (43.9%); Severe: 54/378 (14.3%); Extreme: 4/378 (1.1%); Moderate-to-extreme: 224/378 (59.3%)
Romesser, 2012^44^; n=354; Post-9/11 Veterans assessed at 2 polytrauma clinics. | Self-report | Interference: Asked how much pain interfered with life in the past 30 days (moderately, severely, or extremely versus not at all or mild). | mTBI with no LOC (n=210) vs mTBI with LOC (n=144): Moderately: 72 (34.3%) vs 58 (40.3%) [Total mTBI=36.7%]; Severely: 52 (24.8%) vs 40 (27.8%) [Total mTBI=26.0%]; Extremely: 15 (7.1%) vs 12 (8.3%) [Total mTBI=7.6%]; Severely to extremely: 67 (31.9%) vs 52 (36.1%) [Total mTBI=33.6%]; Moderately to extremely: 139 (66.2%) vs 110 (76.4%) [Total mTBI=70.3%]
Lew, 2009^25^; n=227; Post-9/11 Veterans seen at polytrauma clinic. | EHR data | Presence: Chronic pain was defined as persisting reports of pain in ≥1 body part for ≥3 months after onset. | Total mTBI: 81.9%; mTBI with PTSD: 86.2%; mTBI no PTSD: 70.5%
Powell, 2015^43^; n=171; Post-9/11 Veterans enrolled in VA TRACTS. | EHR/self-report | Presence: Veterans were determined to have chronic pain if pain diagnosis was listed as an active problem in VA EHR and dated prior to TRACTS testing day (n=45); if they were referred to a chronic pain specialist after determined to have chronic pain via clinical interview (n=17); or if they had discussed pain that had lasted ≥3 months during their interview (n=3). | 65/171 (38.0%)
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Self-report telephone interview with openended questions | Bodily pain (other than headache) presence: Any pain in past month. The telephone follow-up interview is an unpublished, 10–15 min, semi-structured interview developed specifically for this study. | 6 mos: 78.3%; 12 mos: 76.4%; 24 mos: 88.9%; 36 mos: 78.6%; 48 mos: 66.7%; 60 mos: 80.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Self-report telephone interview with openended questions | Bodily pain (other than headache) frequency: Daily/almost daily in past month. | 6 mos: 34.8%; 12 mos: 41.6%; 24 mos: 37.0%; 36 mos: NR; 48 mos: 50.0%; 60 mos: Unclear
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Self-report telephone interview with openended questions | Bodily pain (other than headache) intensity: Moderate or greater in past month. | 6 mos: 37.0%; 12 mos: 39.3%; 24 mos: 59.3%; 36 mos: NR; 48 mos: 36.7%; 60 mos: NR

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; EQ-5D-5L=EuroQol Group 5-dimension 5-level version; ICD=International Classification of Diseases; LOC=Loss of consciousness; mTBI=Mild Traumatic Brain Injury; NR=Not reported; OEF=Operation Enduring Freedom; OIF=Operation Iraqi Freedom; PTSD=Posttraumatic Stress Disorder; SM=Servicemember; TRACTS=Translational Research Center for TBI and Stress Related Disorders; VA=Veterans Affairs

#### Head Pain

We identified 23 studies reporting prevalence of head pain in Veterans with a history of mTBI.^6,7,15,39,40,42,44-60^ Headaches and/or migraines were assessed across a range of study populations using a variety of pain assessment tools, including EHR data, the Neurobehavioral Symptom Inventory (NSI), the 15-item Patient Health Questionnaire (PHQ-15), the 6-item Headache Impact Test (HIT-6), and the Post-deployment Health Assessment and Re-assessment (PDHA/PDHRA), with prevalence estimates ranging from 3%^58^ to 98%.^54^ Two studies, 1 larger multi-site study in Air Force SMs (n=5,065)^58^ and 1 very small study in OEF/OIF Veterans from a single site (n=43),^46^ specifically reported the prevalence of migraines independent of headache. The presence of migraines or headaches was combined in 1 large study using administrative data (n=102,055).^45^ All other studies reported prevalence of headaches, although only 9 addressed the severity and/or frequency of headaches.^15,42,46,47,51,53,54,57^

Five studies may best inform prevalence estimates of headache and/or migraine in Veterans with mTBI.^7,39,45,52,53^ These studies were conducted in broad population samples and are most generalizable to the population of SMs/Veterans with mTBI; however, the range of pain prevalence values was broad, from 15% of a SM sample receiving head pain diagnosis codes in a 1-year time period (compared to 3% among those without mTBI diagnosis),^45^ to 94% of Veterans with confirmed mTBI indicating they experience headaches when asked by a clinician completing the CTBIE (compared to 86% of those without confirmed mTBI).^53^ A large (n=102,055) retrospective cohort study of surveillance data from the Defense Medical Surveillance System (DMSS)^45^ estimated a 15% prevalence of headaches or migraines in SMs with a history of mTBI. This was the lowest prevalence estimate among all included studies, with the exception of a smaller study (n=5,065) that reported a prevalence estimate of 3% among SMs in the 31–179-day period post-mTBI.^58^ A similarly large, multi-site, cross-sectional study of 93,003 Veterans estimated a 20% prevalence of headaches among Veterans with mTBI history, compared to 6% of those without.^7^ The prevalence estimate was higher in a multi-site retrospective cohort study of 32,316 Post-9/11 Veterans: 36% of those with mTBI history had a headache diagnosis.^39^ Among Veterans with comorbid mTBI and PTSD diagnosis, the prevalence of headache increased to 48% (compared to 16% among those with PTSD and no mTBI).^39^ In another large study (n=23,703) of Post-9/11 Veterans who were confirmed with mTBI via a completed CTBIE, 70% reported headache pain in the past 30 days, compared to 55% of those without confirmed mTBI.^52^ A smaller study (n=1,683) across 24 VA facilities nationwide also utilized CTBIE data to estimate headache prevalence by intensity and found that approximately 94% of participants experienced any headaches and 82% of participants reported experiencing moderate to very severe headaches (compared to 86% and 61%, respectively, among those without confirmed mTBI).^53^

See Table 4 for additional details of headache/migraine pain measurement and prevalence outcomes for all included studies.

Table 4 Prevalence estimates of head pain from studies of Veterans/Servicemembers with a history of mTBI

Author, year N pts with mTBI Population | Pain assessed by | Pain measurement definition/details of assessment tool | Prevalence Results n (%)
BeswickEscanlar, 2016^45^; n=102,055; SMs. | EHR data | Headache or migraine presence (incident diagnosis; yes.no): Presence/absence of ICD diagnosis code for headache or migraine in EHR during the post-TBI 1-year follow-up period. | 15,519/102,055 (15.2%)
Pugh, 2019^7^; n=93,003; Post-9/11 Veterans. | EHR data | Headache presence (yes/no): ICD diagnosis code in health record during first year of VA care. | 18,929/93,003 (20.4%)
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Headache presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 47.7%; mTBI no PTSD: 36.0%
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Headache presence (yes/no): CTBIE questionnaire item inquires about headache pain in the last 30 days. | 16,534/23,703 (69.8%)
Webb, 2015^58^; n=5,065; Post-9/11 SMs. | EHR data | Headache presence (yes/no): ICD diagnosis code in health record after mTBI diagnosis. | 31–179 days post-mTBI: 142/5,065 (2.8%); ≥180 post-mTBI: 371/5,065 (7.3%)
Webb, 2015^58^; n=5,065; Post-9/11 SMs. | EHR data | Migraine presence (yes/no): ICD diagnosis code in health record after mTBI diagnosis. | 31–179 days post-mTBI: 79/5,065 (1.6%); ≥180 days post-mTBI: 211/5,065 (4.2%)
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE (headache item from NSI) | Headache presence (yes/no) and severity: Presence and severity were evaluated at the baseline CTBIE assessment using the NSI 5-level headache item ranging from 0 (“none”) to 4 (“very severe”) interference in past 30 days. | Any headache: 94.1%; Severity:; Mild: 12.5%; Moderate: 26.8%; Severe: 33.7%; Very severe: 21.1%; Total Mod-Severe: 81.6%
Tsao, 2017^55^; n=1,022; Post-9/11 SMs. | Self-report | Headache presence (yes/no): Survey asked if respondents experienced headaches (yes/no). | 1 mTBI: 499/892 (55.9%); ≥2 mTBI: 96/130 (73.8%); Total any # of mTBI:; 595/1,022 (58.2%)
Theeler, 2012^54^; n=978; Post-9/11 SMs. | Self-report | Headache presence (yes/no): Assessed using 13-item self-administered headache questionnaire in TBI clinic. Chronic daily headaches (CDH; defined as headaches occurring ≥15 days per month for the previous 3 months); episodic headaches were<15 days/month. Also measured headaches meeting criteria for migraine, post-traumatic headache (PTHA), and headaches that disrupt functioning. | Total headache: 957/978 (97.9%); CDH: 196/978 (20.0%); Episodic headache: 761/978 (77.8%); Migraine: 504/978 (51.5%); PTHA: 360/978 (36.8%); Disrupt functioning: 397/978 (40.6%)
Jackson, 2016^48^; n=612; Post-9/11 Veterans. | EHR data/Self-report | Headache presence (yes/no): Assessed as part of the VA TBI Clinical Reminder and Screening Tool (endorsed symptoms after injury and currently). | Total mTBI: 196/592 (33.1%); mTBI+PTSD: 151/384 (39.3%); mTBI no PTSD: 45/208 (21.6%)
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Headache presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 144/563 (25.6%); LOC: 72/197 (36.5%); AOC: 72/366 (19.7%)
Schwab, 2017^51^; n=557; Post-9/11 SMs. | NSI | Headache intensity: Proportion that rated item on the NSI for headaches as a 3 or 4 (severe or very severe) on a 0–4 scale, 3-months post-deployment (and post-TBI screening). | 15% of 358 who completed 3-month follow-up.
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Headache presence (yes/no): If treated for headache conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI:; 160/421 (38.0%); mTBI+PTSD:; 145/283 (51.2%)
Walker, 2018a^57^; n=414; Post-9/11; Veterans/SMs. CENC sample. | HIT-6 | Headache impact on function, categorized as: No headaches lately; Little to no impact; Some impact; Substantial impact; Very severe impact. | Some impact:; 44/407 (10.8%); Substantial impact:; 50/407 (12.3%); Very severe impact: 172/407 (42.3%); Some to very severe headache impact: 266/407 (65.4%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Headache presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 84/375 (22.4%); LOC: 39/121 (32.2%); AOC: 45/254 (17.7%)
Romesser, 2012^44^; n=354; Post-9/11 Veterans assessed at 2 polytrauma clinics. | Self-report | Headache presence (yes/no): If Veteran reported problems with pain in the past 30 days, self-reported information about pain characteristics was used to classify the individual with head pain/headaches. | Total mTBI: 266/354 (75.1%); LOC: 116/144 (80.6%); No LOC: 150/210 (75.1%)
MacGregor, 2013^49^; n=334; Post-9/11 SMs. | PDHRA | Headache presence (yes/no): Asked to endorse whether they currently have headache pain that they feel is related to their deployment. | Total mTBI: 111/334 (33.2%); mTBI with LOC: 37/103 (35.9%); mTBI no LOC: 43/150 (28.7%)
Vanderploeg, 2009^56^; n=278; Vietnam-era Veterans. | Self-report | Headache presence (yes/no): Medical history interview and questionnaire: “During the past year, have you had unusually frequent or severe headaches?”. | 27.0%
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Headache presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 85/260 (32.7%); LOC: 40/86 (46.5%); AOC: 45/174 (25.9%); mTBI+PTSD: 53/96 (55.2%); mTBI no PTSD: 31/163 (19.0%)
Patil, 2011^50^; n=246; Post-9/11 Veterans seen in Polytrauma clinic. | CTBIE and EHR | Headache presence (yes/no): Asked if they experienced headache pain within the 30 days preceding the CTBIE. Among Veterans who were referred to and attended a Neurology clinic evaluation, diagnoses of migraine, chronic daily headache (CDH), and post-traumatic headache (PTHA) were measured. | CTBIE: 182/246 (74.0%); Received and attended Neurology clinic referral: 56/246 (22.8%); Migraine: 25/56 (44.6%); CDH: 11/56 (19.6%); PTHA: 4/56 (7.1%)
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Headache presence (yes/no): Any in past month. (the telephone follow-up interview is an unpublished, 10–15 min, semi-structured interview developed specifically for this study.) | 6 mos: 73.9%; 12 mos: 67.4%; 24 mos: 85.2%; 36 mos: 83.3%; 48 mos: 83.3%; 60 mos: 92.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Headache frequency: Daily or weekly in past month. | 6 mos: 58.7%; 12 mos: 56.2%; 24 mos: 64.8%; 36 mos: 64.3%; 48 mos: 70.0%; 60 mos: 76.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Headache intensity: Moderate or higher in past month. | 6 mos: 52.2%; 12 mos: 41.6%; 24 mos: 53.7%; 36 mos: 59.5%; 48 mos: 63.3%; 60 mos: 68.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Pain location: Any (non-headache) head or neck pain in past month. | 6 mos: 17.4%; 12 mos: 18.0%; 24 mos: 16.7%; 36 mos: 7.1%; 48 mos: 20.0%; 60 mos: 4.0%
Ruff, 2008^6^; n=126; Post-9/11 Veterans seen in a polytrauma clinic. | Neurological exam | Headache presence (yes/no): Present and associated with Post-9/11 deployment. Among Veterans with headache, proportions with diagnoses of migraine, tension, or mixed headache presented. | Any headache: 80/126 (63.5%); Migraine: 14/126 (11.1%); Tension: 36/126 (28.6%); Mixed: 30/126 (23.8%)
Couch, 2016^46^; n=43; Post-9/11 Veterans. | Self-report during clinical assessment | Headache frequency: Chronic daily headaches (CDH; defined as ≥15 days/month) or frequent headaches (defined as 10–14 days/month) in 6 months prior to telephone questionnaire. (Used detailed headache questionnaire which has been used in the University of Oklahoma Headache Clinic since 1996.) | All mTBI:; CDH: 18/43 (41.9%); Frequent headache: 16/43 (37.2%); Either CDH or FH: 34/43 (79.1%); mTBI with LOC:; CDH: 11/23 (47.8%); Frequent headache: 6/23 (26.1%); mTBI with AOC:; CDH: 7/20 (35.0%); Frequent headache: 10/20 (50.0%)
Couch, 2016^46^; n=43; Post-9/11 Veterans. | Self-report during clinical assessment. | Tension headache presence (yes/no): Determined by headache questionnaire and based on the hierarchical method of the ICDH-3 system. | All mTBI: 4/43 (9.3%); mTBI with LOC: 2/23 (8.7%); mTBI with AOC: 2/20 (10.0%)
Couch, 2016^46^; n=43; Post-9/11 Veterans. | Self-report during clinical assessment. | Migraine (with & without aura) presence (yes/no): Determined by headache questionnaire and based on the hierarchical method of the ICDH-3 system. | All mTBI: 38/43 (88.4%); mTBI with LOC: 21/23 (91.3%); mTBI with AOC: 17/20 (85.0%)
Farrell-Carnahan, 2015^47^; N=40; VA PRC TBIMS. | NSI | Headache intensity: NSI Item 4 ‘severely’/‘very severely’ disturbed by headaches in the last 2 weeks. | 11/40 (27.5%)

Abbreviations: AOC=Alteration of consciousness; CDH=Chronic daily headaches; EHR=Electronic Health Record; FH=Frequent headaches; HIT-6=Headache Impact Test; ICDH-3=The International Classification of Headache Disorders 3rd edition; LOC=Loss of consciousness; mTBI=Mild Traumatic Brain Injury; NSI=Neurobehavioral Symptom Inventory; OEF=Operation Enduring Freedom; OIF=Operation Iraqi Freedom; PDHRA=Post-Deployment Health Re-Assessment; PHQ-15=15-item Patient Health Questionnaire scale; PRC=Polytrauma Rehabilitation Center; PTHA=Posttraumatic headaches; SM=Servicemember; TBI=Traumatic Brain Injury; TBIMS=Traumatic Brain Injury Model Systems; VA=Veterans Affairs; VALOR=Veterans’ After-discharge Longitudinal Registry

#### Back pain

We included 10 studies that reported measures of back pain prevalence among Veterans and SMs with mTBI.^7,15,40,44,49,52,53,56,59,60^ These studies ranged in size from clinical samples of 260 to large database studies of 93,003. Pain assessment varied broadly across studies and included validated measures of pain presence, standardized measures used in surveillance and screening instruments, and ICD diagnosis codes from healthcare records.

Three studies involved similar Post-9/11 SM populations and methodology, including assessment of pain using the PHQ-15, and may provide the most consistent evidence for prevalence of chronic back pain.^15,59,60^ Prevalence levels of back pain among SMs with mTBI in these 3 studies ranged from 32% to 44%. These studies also reported prevalence levels stratified by mTBI with loss of consciousness (LOC) versus alteration of consciousness (AOC); the prevalence of back pain was consistently higher among those with LOC than those with AOC, but only slightly so. Wilk et al, 2012^59^ also stratified prevalence levels by mTBI with, versus without, comorbid PTSD and prevalence of back pain was considerably higher among those with comorbid PTSD (56% versus 36%).

Using data from the VA CTBIE, which asks about pain in the past 30 days, 2 studies by Suri et al^52,53^ also report relatively consistent findings. In these 2 samples, 13%^52^ and 16%^53^ of Veterans with mTBI reported the presence of upper back pain (versus 11%, in both studies, among those without confirmed mTBI) and 53%^52^ and 58%^53^ reported the presence of lower back pain (versus 48%, in both studies, of those without confirmed mTBI). Romesser et al reported somewhat similar, although higher, figures for a sample of Post-9/11 Veterans treated at 2 polytrauma clinics.^44^ Based on a clinical questionnaire used with these treatment-seeking Veterans, 21% experienced upper back pain and 61% experienced lower back pain. This compared to 13% and 56% among those who did not have a history of mTBI.

Two studies were based on VA EHR data and reported prevalence of back pain diagnoses among Post-9/11 Veterans.^7,40^ Pugh et al used data for only the first year of Veterans’ VA use and reported a prevalence of 27% among 93,003 Veterans with mTBI (compared to 18% among Veterans without any indication of mTBI history).^7^ King et al used data for multiple years of VA use and reported a prevalence of 46% among 421 Veterans with mTBI history (versus 23% of those without).^40^

Additional details of these and other studies presenting back pain data are presented in Table 5.

#### Neck pain

Five studies reported data on prevalence of neck pain among Veterans with mTBI; all 5 involved Post-9/11 VA patients.^7,40,44,52,53^ Two studies were based on VA EHR data and reported prevalence of neck pain diagnoses.^7,40^ Pugh et al used data for only the first year of Veterans’ VA use and reported a prevalence of 6% among 93,003 Veterans with mTBI history (and 3% among 434,378 Veterans without mTBI),^7^ while King et al used data for multiple years of VA use and reported a prevalence of 14% among 421 Veterans (and 6% among a matched sample of 421 Veterans without mTBI).^40^ Two studies by Suri et al^52,53^ used data from the VA CTBIE, which asks about pain in the past 30 days. In these 2 samples, 23%^52^ and 30%^53^ of those with clinician-confirmed mTBI reported the presence of neck pain, while only 19% and 21% of those without clinician-confirmed mTBI reported neck pain. The highest prevalence of neck pain was observed in a sample of 354 Veterans seeking care in VA polytrauma clinics,^44^ in which 40% reported that they had experienced neck pain in the past 30 days on a clinical questionnaire (45% among those who experienced LOC with their mTBI and 37% among those who did not; in comparison, 29% of Veterans without mTBI history reported neck pain).

#### Arm, leg, and/or joint pain

Arm, leg and/or joint pain were reported in 9 studies.^15,39,42,49,52,53,56,59,60^ Outcomes were assessed differently across studies, both in terms of what qualified as chronic arm, leg, or joint pain and the specific parts of the arms, legs, and/or joints that the studies assessed.

The largest study involved 32,316 Post-9/11 Veterans and used 1 year of VA EHR data to estimate prevalence of musculoskeletal pain among patients with mTBI.^39^ Almost 39% of Veterans diagnosed with mTBI were diagnosed with musculoskeletal pain; among Veterans diagnosed with both mTBI and PTSD, 47% were also diagnosed with musculoskeletal pain (versus 35% of those with PTSD diagnoses only). This study defined both mTBI and pain (and PTSD) as any single instance of a respective ICD diagnosis code in the Veterans’ health record.

Three studies^15,59,60^ assessed pain using the PHQ-15, which asks about “Arm/leg/joint pain” intensity in the past month. For the purposes of these studies, those who ranked their pain intensity as “bothered a lot” were considered to have chronic pain. All 3 studies reported prevalence levels of arm/leg/joint pain between 40% and 50%. These studies stratified the mTBI sample by those who had experienced an LOC at the time of their mTBI versus those who experienced AOC.^15,59,60^ In 2 of the studies,^59,60^ prevalence estimates were slightly higher for those with LOC versus those with AOC; the opposite was observed in the third study.^15^ One study also stratified the sample by whether comorbid PTSD was present.^59^ As with other types of chronic pain, reports of arm/leg/joint pain were considerably more prevalent among those with comorbid PTSD than among those without (66% and 41%, respectively).

Two large studies using CTBIE data reported on “other joint pain,” defined as pain experienced in the legs, arms, hands, feet, or “other” locations in the past 30 days.^52,53^ Prevalence levels in these studies were fairly similar for those with clinician-confirmed mTBI (48% and 53%), with both estimates slightly higher than among those without confirmed mTBI (44% and 43%). These 2 studies also reported on shoulder pain and, again, presented similar results (25% and 30%, versus 21% and 22%).

Several smaller studies reported on pain in various joints and parts of the arms and legs (eg, shoulders, knees, hips). See Table 5 for details of pain measurement and prevalence outcomes in these and all other included studies.

#### Abdominal/stomach pain

Five studies reported prevalence of abdominal or stomach pain among Veterans and SMs with mTBI.^15,40,56,59,60^ All reported prevalence levels that were, in general, 10% or less. Among these studies, 3 involved similar Post-9/11 SM study populations and methodology;^15,59,60^ prevalence ranged from 7% to 9% (these estimates were slightly higher than those provided in the 2 studies that also reported prevalence among participants without mTBI). These studies also reported prevalence stratified by mTBI with LOC versus mTBI with AOC and, in general, abdominal pain prevalence was slightly higher among those with LOC versus AOC. A study by Wilk et al^59^ also stratified prevalence levels by mTBI with, versus without, comorbid PTSD and prevalence was considerably higher among those with comorbid PTSD (12% versus 5%). Another study examined VA healthcare records for Post-9/11 Veterans ^40^ and reported that 3% of those diagnosed with post-concussion syndrome had also been diagnosed with abdominal pain. Finally, a 1980s study of Vietnam-era Veterans reported abdominal pain in 10% of those with a history of mTBI (versus 12% among those with other injuries but without mTBI).^56^

#### Arthritis

Two studies reported prevalence of arthritis (considered an indicator of chronic pain) among individuals with mTBI.^40,57^ Both were smaller studies with similar sample sizes, 414^57^ and 421,^40^ and reported fairly consistent prevalence estimates of 44% and 41% respectively. These estimates were higher than estimates among participants in these studies without mTBI (30% and 33%, respectively). The smaller study used CENC data for prevalence of arthritis,^57^ and the larger used VA EHR data to estimate the presence of arthritis for at least 3 months.^40^

#### Chest pain

Three studies involving similar Post-9/11 SM study populations and methodology reported on chest pain.^15,59,60^ Prevalence levels among SMs with mTBI in these 3 studies ranged from 6% to 12%. Two studies included estimates for comparison groups with other (non-mTBI) injuries (4% and 5%) or with no injuries (4% and 2%). These studies also reported prevalence levels stratified by mTBI with LOC versus AOC; as reported above, the prevalence of chest pain was consistently slightly higher among those with LOC than those with AOC. Wilk et al, 2012^59^ also stratified prevalence levels by mTBI with, versus without, comorbid PTSD and prevalence was 2 times higher among those with comorbid PTSD (19% versus 8%).

#### Pain medication use

Use of pain medications, abstracted as an indicator of chronic pain, was reported in 4 articles.^40-42,54^ Three studies were clinic-based and enrolled Post-9/11 Veterans/SMs,^41,42,54^ while the other study was based on EHR data for Post-9/11 Veterans.^40^ In an analysis of CENC study data, Hoot et al^41^ reported that 50% of 379 participants with mTBI were using analgesic pain medications, compared to 32% of those without a history of mTBI. Brickell et al^42^ queried 167 Post-9/11 SMs with mTBI and polytrauma who participated in follow-up telephone interviews. Among the 46 participants interviewed within 6 months of their injury, 30% reported using prescription opioid medications and 100% reported using non-opioid pain medications. Finally, in a clinical study of 978 SMs who screened positive for mTBI and were evaluated in a TBI program,^54^ 50% of the 196 with chronic daily headaches (and 11.6% of the entire mTBI sample) reported using abortive headache medications for 15 or more days per month in the prior 3 months. A study based on VA EHR data for Post-9/11 Veterans with diagnosed post-concussion syndrome in the Northeast region of the US reported that 78% had received any kind of pain control prescription medication; 49% were prescribed opioid analgesics, 29% non-opioid analgesics, 58% nonsteroidal anti-inflammatory drugs (NSAIDs), and 17% anti-migraine agents.^40^ This study also stratified medication receipt by comorbid PTSD diagnosis status and, with the exception of NSAID medications, pain medication prescriptions were more prevalent among Veterans with comorbid PTSD than those without.

#### Sexual pain/problems

The 3 studies involving similar Post-9/11 SM study populations and methodology also reported on sexual pain/problems.^15,59,60^ The prevalence levels among SMs with mTBI in these studies ranged from 5% to 9%. These estimates were slightly higher than those from the 2 studies that provided an injured (but no mTBI) comparison group (5% and 4%) and a non-injured (2% and 1%) comparison group. These studies also reported prevalence levels stratified by mTBI with LOC versus AOC and, again, the prevalence of sexual pain/problems was consistently slightly higher among those with LOC than those with AOC. Wilk et al 2012^59^ also stratified prevalence levels by mTBI with, versus without, comorbid PTSD and prevalence was considerably higher among those with comorbid PTSD (22% versus 3%). Of note, the vast majority (91% to 99%) of participants in these 3 studies were male.

#### Other pain

A small number of studies reported other pain types not otherwise categorized above.^7,39,40,42^ Data from these studies are presented in Table 5.

Table 5 Prevalence estimates of other chronic pain from studies of Veterans and Servicemembers with a history of mTBI

Author, year N pts with mTBI Population | Pain assessed by | Pain measurement definition/details of assessment tool | Prevalence Results n (%)
Back Pain
Pugh, 2019^7^; n=93,003; Veterans. | EHR data | Back pain presence (yes/no): ICD diagnosis code in health record during first year of VA care. | 25,255/93,003 (27.2%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | EHR data | Back pain presence (yes/no): VA health care use for back pain in past year. | 8,661/23,703 (36.5%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Back pain presence (yes/no): Indicate whether experienced in last 30 days. | 13,303/23,703 (56.1%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Low back pain (yes/no) | 12,498/23,703 (52.7%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Upper back pain (yes/no) | 3,162/23,703 (13.3%)
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Back pain presence (yes/no): Indicate whether experienced in last 30 days. | 60.9%
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Low back pain (yes/no) | 57.5%
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Upper back pain (yes/no) | 15.6%
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Back pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 205/562 (36.5%); LOC: 85/197 (43.1%); AOC: 120/365 (32.8%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Back pain presence (yes/no): If treated for back pain conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI: 193/421 (45.8%); mTBI+PTSD: 170/283 (60.1%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Back pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 118/374 (31.6%); LOC: 40/121 (33.1%); AOC: 78/253 (30.8%)
Romesser, 2012^44^; n=354; Post-9/11 Veterans assessed at 2 polytrauma clinics. | Self-report | Low back pain presence (yes/no): If Veteran reported problems with pain in the past 30 days, self-reported information about pain characteristics was used to classify the individual with low back pain. | Total mTBI: 216/354 (61.0%); LOC: 90/144 (62.5%); No LOC: 126/210 (60.0%)
Romesser, 2012^44^; n=354; Post-9/11 Veterans assessed at 2 polytrauma clinics. | Self-report | Upper back pain presence (yes/no): Same as above. | Total mTBI: 73/354 (20.6%); LOC: 34/144 (23.6%); No LOC: 39/210 (18.6%)
MacGregor, 2013^49^; n=334; Post-9/11 SMs. | PDHRA | Back pain presence (yes/no): Asked to endorse whether they currently have pain that they feel is related to their deployment. | Total mTBI: 110/334 (32.9%); mTBI with LOC: 31/103 (30.1%); mTBI no LOC: 49/150 (32.7%)
Vanderploeg, 2009^56^; n=278; Vietnam-era Veterans. | Self-report | Low back pain presence (yes/no): Unusually frequent or severe pain during last year via medical history interview and questionnaire. | 36.3%
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Back pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 114/260 (43.8%); LOC: 39/86 (45.3%); AOC: 75/174 (43.1%); mTBI+PTSD: 54/96 (56.3%); mTBI no PTSD: 59/163 (36.2%)
Neck Pain
Pugh, 2019^7^; n=93,003; Post-9/11 Veterans. | EHR data | Neck pain presence (yes/no): ICD diagnosis code in health record during first year of VA care. | 5,916/93,003 (6.4%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Neck pain presence (yes/no): Indicate whether experienced in last 30 days. | 5,428/23,703 (22.9%)
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Neck pain presence (yes/no): Indicate whether experienced in last 30 days. | 30.4%
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Neck pain presence (yes/no): If treated for neck pain conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI: 57/421 (13.5%); mTBI+PTSD: 50/283 (17.7%)
Romesser, 2012^44^; n=354; Post-9/11 Veterans assessed at 2 polytrauma clinics. | Self-report | Neck pain presence (yes/no): If Veteran reported problems with pain in the past 30 days, self-reported information about pain characteristics was used to classify the individual with neck pain. | Total mTBI: 143/354 (40.4%); LOC: 65/144 (45.1%); No LOC: 78/210 (37.1%)
Arm/leg/joint pain
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Musculoskeletal pain presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 47.0%; mTBI no PTSD: 38.8%
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Shoulder pain presence (yes/no): Indicate whether experienced in last 30 days. | 5,799/23,703 (24.5%)
Suri, 2019^52^; n=23,703; Post-9/11 Veterans. | CTBIE | Other joint pain (legs, arms, hands, feet, or “other” location) presence (yes/no): Indicate whether experienced in last 30 days. | 11,357/23,703 (47.9%)
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Shoulder pain presence (yes/no): Indicate whether experienced in last 30 days. | 30.0%
Suri, 2017^53^; n=1,683; Post-9/11 Veterans. | CTBIE | Other joint pain (legs, arms, hands, feet, or “other” location) presence (yes/no): Indicate whether experienced in last 30 days. | 53.1%
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Arm/leg/joint pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 254/559 (45.4%); LOC: 95/196 (48.5%); AOC: 159/363 (43.8%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Arm/leg/joint pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 150/373 (40.2%); LOC: 45/121 (37.2%); AOC: 105/252 (41.7%)
Vanderploeg, 2009^56^; n=278; Vietnam-era Veterans. | Self-report | Calf pain presence (yes/no): Unusually frequent or severe pain during last year via medical history interview and questionnaire. | 4.4%
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Arm/leg/joint pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 129/260 (49.6%); LOC: 47/86 (54.7%); AOC: 82/174 (47.1%); mTBI+PTSD: 63/96 (65.6%); mTBI no PTSD: 66/163 (40.5%)
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions. | Lower extremities pain (yes/no): Any pain in past month (the telephone follow-up interview is an unpublished, 10–15 min, semi-structured interview developed specifically for this study). | 6 mos: 43.5%; 12 mos: 37.1%; 24 mos: 55.6%; 36 mos: 28.6%; 48 mos: 23.3%; 60 mos: 28.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions. | Upper extremities pain (yes/no). | 6 mos: 26.1%; 12 mos: 24.7%; 24 mos: 25.9%; 36 mos: 19.0%; 48 mos: 23.3%; 60 mos: 8.0%
MacGregor, 2013^49^; n=334; Post-9/11 SMs. | PDHRA | Joint and muscle pain presence (yes/no): Asked to endorse whether they currently have pain that they feel is related to their deployment. | Total mTBI: 78/334 (23.4%); mTBI with LOC: 25/103 (24.3%); mTBI no LOC: 49/150 (32.7%)
Abdominal/stomach pain
Vanderploeg, 2009^56^; n=278; Vietnam-era Veterans. | Self-report | Abdominal pain presence (yes/no): Unusually frequent or severe pain during last year via medical history interview and questionnaire. | 10.1%
^40^; n=421; Post-9/11 Veterans. | EHR data | Abdominal pain presence (yes/no): If treated for abdominal pain conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI: 12/421 (2.9%); mTBI+PTSD: 11/283 (3.9%)
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Stomach pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 47/557 (8.4%); LOC: 17/196 (8.7%); AOC: 30/361 (8.3%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Stomach pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 34/369 (9.2%); LOC: 14/120 (11.7%); AOC: 20/249 (8.0%)
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Stomach pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 19/260 (7.3%); LOC: 5/86 (5.8%); AOC: 14/174 (8.0%); mTBI+PTSD: 11/96 (11.5%); mTBI no PTSD: 8/163 (4.9%)
Arthritis
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR | Arthritis presence (yes/no): If treated for arthritis conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI: 173/421 (41.1%); mTBI+PTSD: 152/283 (53.7%)
Walker, 2018a^57^; n=414; Post-9/11 Veterans/SMs. CENC sample | BRFSS | Arthritis presence (yes/no): This item was asked as in the CDC’s Behavioral Risk Factor Surveillance System: “Has a doctor, nurse, or other health professional EVER told you that you had any of the following? For each, tell me ‘Yes,’ ‘No,’ or you’re ‘Not sure.’” Variable was dichotomous. | 180/412 (43.7%)
Chest Pain
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Chest pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 46/560 (8.2%); LOC: 28/196 (14.3%); AOC: 18/364 (4.9%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Chest pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 24/374 (6.4%); LOC: 17/121 (14.0%); AOC: 7/253 (2.8%)
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Chest pain presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 30/260 (11.5%); LOC: 11/86 (12.8%); AOC: 19/174 (10.9%); mTBI+PTSD: 18/96 (18.8%); mTBI no PTSD: 13/163 (8.0%)
Pain medication use
Theeler, 2012^54^; n=978; Post-9/11 SMs. | Self-report | Abortive headache medication use among those with chronic daily headaches (CDH; ≥15 days/month for past 3 months; n=196) versus those with episodic headaches (<15 days/month; n=761). | Total mTBI: 113/978 (11.6%); CDH: 97/196 (49.5%); Episodic headache: 16/761 (2.1%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Any pain control medication prescriptions identified in VA pharmacy records (yes/no). | Total mTBI: 312/400 (78.0%); TBI+PTSD: 277/351 (78.9%); TBI no PTSD: 35/49 (71.4%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Opioid analgesic prescriptions identified in VA pharmacy records (yes/no). | Total mTBI: 195/400 (48.8%); TBI+PTSD: 174/351 (49.6%); TBI no PTSD: 21/49 (42.9%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Non-opioid analgesics prescriptions identified in VA pharmacy records (yes/no). | Total mTBI: 117/400 (29.3%); TBI+PTSD: 104/351 (29.6%); TBI no PTSD: 13/49 (26.5%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Non-steriodal anti-inflamatory drug prescriptions identified in VA pharmacy records (yes/no). | Total mTBI: 231/400 (57.8%); TBI+PTSD: 103/351 (29.3%); TBI no PTSD: 29/49 (59.2%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Anti-migraine agent prescriptions identified in VA pharmacy records (yes/no). | Total mTBI: 66/400 (16.5%); TBI+PTSD: 59/351 (16.8%); TBI no PTSD: 7/49 (14.3%)
Hoot, 2018^41^; n=379; Post-9/11 Veterans/SMs. CENC sample | EHR/Self-report | Analgesic medication use (yes/no): Uses analgesic medications. | 188/376 (50.0%)
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Opioid pain medication use (yes/no): Asked if taking any medications and categorized post hoc. The telephone follow-up interview is an unpublished, 10–15 min, semi-structured interview developed specifically for this study. | 6 mos: 30.4%; 12 mos: 25.8%; 24 mos: 18.5%; 36 mos: 19.0%; 48 mos: 26.7%; 60 mos: 12.0%
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Other (non-opioid) pain medication use (yes/no): Asked if taking any medications for pain and categorized post hoc. | 6 mos: 100%; 12 mos: 27.0%; 24 mos: 18.5%; 36 mos: 19.0%; 48 mos 30.0%; 60 mos: 8.0%
Sexual pain/problems
Wilk, 2010^60^; n=587; Post-9/11 SMs. | PHQ-15 | Sexual pain/problems presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 33/560 (5.9%); LOC: 16/196 (8.2%); AOC: 17/364 (4.7%)
Hoge, 2008^15^; n=384; Post-9/11 SMs. | PHQ-15 | Sexual pain/problems presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 18/373 (4.8%); LOC: 10/120 (8.3%); AOC: 8/253 (3.2%)
Wilk, 2012^59^; n=260; Post-9/11 SMs. | PHQ-15 | Sexual pain/problems presence in past month (yes/no): “Bothered a lot”=yes. | Total mTBI: 23/260 (8.8%); LOC: 9/86 (10.5%); AOC: 14/174 (8.0%); mTBI+PTSD: 21/96 (21.9%); mTBI no PTSD: 4/163 (2.5%)
Other
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Skeletal pain presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 3.1%; mTBI no PTSD: 2.1%
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Diabetic pain presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 0.3%; mTBI no PTSD: 0.2%
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Fibromyalgia presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 4.1%; mTBI no PTSD:2.2%
Kulas, 2018^39^; n=32,316; Post-9/11 Veterans. | EHR data | Herpetic pain presence (yes/no): Presence/absence of ICD diagnosis code in EHR. | mTBI+PTSD: 1.1%; mTBI no PTSD: 0.6%
Pugh, 2019^7^; n=93,003; Post-9/11 Veterans. | EHR data | Other pain presence (arthritis/musculoskeletal pain; yes/no): ICD diagnosis code in health record during first year of VA care. | 19,631/93,003 (21.1%)
King, 2014^40^; n=421; Post-9/11 Veterans. | EHR data | Other pain presence (yes/no): If treated for other pain conditions for ≥3 months based on ICD diagnosis codes (ie, if the time elapsed between encounters with similarly coded conditions was ≥90 days from the initial encounter). | Total mTBI: 107/421 (25.4%); mTBI+PTSD: 99/283 (35.0%)
Brickell, 2014^42^; n=167; Post-9/11 SMs. | Telephone interview with open-ended questions | Body pain (as contrasted with extremities and head and neck pain) presence (yes/no): Any pain in past month (the telephone follow-up interview is an unpublished, 10–15 min, semi-structured interview developed specifically for this study). | 6 mos: 43.5%; 12 mos: 40.4%; 24 mos: 37.0%; 36 mos: 38.1%; 48 mos: 40.0%; 60 mos: 16.0%

Abbreviations: AOC=Alteration of consciousness; BRFSS=Behavioral Risk Factor Surveillance System; CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; ICD=International Classification of Diseases; LOC=Loss of consciousness; PDHRA=Post-Deployment Health Re-Assessment; PHQ-15=15-item Patient Health Questionnaire scale; PTSD=Posttraumatic stress disorder; SM=Servicemember; VA=Veterans Affairs

#### KQ1a What are the most common types of chronic pain in US Veterans or Servicemembers with a history of mTBI?

Across studies, back pain, head pain, and arm, leg, and/or joint pain were the most prevalent types of chronic pain observed. For instance, 1 study of 384 SMs with a history of mTBI^15^ asked how much they were bothered by physical symptoms in the past month (PHQ-15) including stomach pain, back pain, arm, leg, or joint pain, headache, and chest pain. Of those with a history of mTBI, arm, leg, or joint pain was the most prevalent (40.2% indicated they were “bothered a lot”), followed by back pain (31.6%), then headache (22.4%). See Table 4 and Table 5 for more details.

#### KQ1b Do the prevalence or types of chronic pain experienced by US Veterans or Servicemembers with a history of mTBI differ by mTBI etiology?

Three studies^41,46,60^ provide evidence for prevalence of chronic pain in Veterans and SMs with a history of mTBI by mTBI etiology. Table 6 summarizes the results of these studies. All included studies examined mTBI due to blast compared to mTBI resulting from non-blast causes; no other etiologies were examined/compared. Overall, blast-related mTBI did not appear to be associated with more frequent or more severe pain in these 3 studies. One exception was the measure of headache prevalence in Wilk et al 2010^60^ which, among Veterans who experienced LOC after their mTBI (but not those who only experienced AOC), was endorsed for 40% of those whose mTBI was associated with blasts versus only 23% of those whose mTBI was not associated with blasts. None of the other pain types assessed in this study differed by mTBI etiology. The study by Hoot et al^41^ may also suggest higher pain prevalence among those with blast versus non-blast mTBI; however, this difference was small (eg, 63% versus 56%). None of the studies compared pain prevalence levels by location of mTBI, location of co-occurring injuries, or timing of pain onset relative to the mTBI.

Table 6 Prevalence of Chronic Pain in Veterans and Servicemembers with a History of mTBI by mTBI Etiology

Author, year N pts with mTBI Population | mTBI etiology assessed by | mTBI etiology measurement/assessment tool | Pain assessed by | Pain measurement definition/details of assessment tool | Pain prevalence results by etiology n (%)
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Stomach pain presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 13/156 (8.3%) vs 4/40 (10.0%); P=0.76; AOC blast vs non-blast: 14/254 (5.5%) vs 16/107 (15.0%); P=0.01
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Back pain presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 71/157 (45.2%) vs 14/40 (35.0%); P=0.29; AOC blast vs non-blast: 84/257 (32.7%) vs 36/108 (33.3%); P=0.90
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Arm/leg/joint pain presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 78/156 (50.0%) vs 17/40 (42.5%); P=0.48; AOC blast vs non-blast: 105/256 (41.0%) vs 54/107 (50.5%); P=0.11
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Headache presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 63/157 (40.1%) vs 9/40 (22.5%); P=0.04; AOC blast vs non-blast: 53/258 (20.5%) vs 19/108 (17.6%); P=0.57
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Chest pain presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 23/156 (14.7%) vs 5/40 (12.5%); P=0.81; AOC blast vs non-blast: 12/258 (4.7%) vs 6/106 (5.7%); P=0.79
Wilk, 2010^60^; n=587; Post-9/11 SMs. | Self-report | The questionnaire (3–6 months after return from deployment) asked soldiers whether they had been injured during deployment by a blast/explosion. | PHQ-15 | Abdominal pain presence in past month (yes/no): “Bothered a lot”=yes. | LOC blast vs non-blast: 13/156 (8.3%) vs 3/40 (7.5%); P=1.00; AOC blast vs non-blast: 13/257 (5.1%) vs 4/107 (3.7%); P=0.79
Hoot, 2018^41^; n=379; Post-9/11 Veterans/SMs. CENC sample. | VCU rCDI | Detailed structured diagnostic TBI interview for blast or non-blast TBI. | EQ-5D-5L | Pain presence and intensity: Moderate, severe, or extreme level of pain or discomfort. | mTBI by blast exposure:; ≥1 TBI from blast: 123/196 (62.8%); TBI not from blast: 101/182 (55.5%); Severity breakdown:; (≥1 TBI from blast vs TBI not from blast):; Moderate pain or discomfort: 83/196 (42.3%) vs 83/182 (45.6%); Severe pain or discomfort: 37/196 (18.9%) vs 17/182 (9.3%); Extreme pain or discomfort: 3/196 (1.5%) vs 1/182 (0.5%)
Couch, 2016^46^; n=43; Post-9/11 Veterans. | Self-report | Screening questionnaire in TBI clinic: Mode of injury recorded including number of blast injuries versus blunt injury with no blast. | Self-report | Detailed headache questionnaire which has been used in the University of Oklahoma Headache clinic since 1996: Assessed chronic daily headache (CDH, defined as ≥15 days/month) and frequent headache (defined as 10–14 days/month) in the last 6 months prior to telephone contact (questionnaire). | CDH:; Blast mTBI: 15/34 (44.1%); Blunt mTBI-only: 4/9 (44.4%); Frequent headache:; Blast mTBI: 12/34 (35.3%); Blunt mTBI-only: 3/9 (33.3%)

Abbreviations: AOC=Alteration of consciousness; CDH=Chronic daily headaches; EQ-5D-5L=EuroQol Group 5-dimension 5-level version quality-of-life; LOC=Loss of consciousness; mTBI=Mild traumatic brain injury; PHQ-15=15-Item Patient Health Questionnaire; SM=Servicemember; TBI=Traumatic brain injury; VCU-rCDI=Virginia Commonwealth University retrospective Concussion Diagnostic Interview

#### KQ1c How do estimates of the prevalence of chronic pain and mTBI in US Veterans or Servicemembers differ according to pain measurement methods or definitions?

Studies of pain prevalence in populations with a history of mTBI (ie, those included for KQ1) employed a wide variety of strategies to assess pain. These strategies include self-report, use of validated measures, diagnostic data abstraction from the EHR, and evaluation of medication use for pain. Within types of measures used, there was also variability, as some studies required a certain threshold of symptoms (such as endorsement of at least “bothered a lot” on the PHQ-15), whereas other studies identified pain regardless of the level of severity (such as “frequent headache” in the past month). There was also heterogeneity in strategies for identifying pain from the EHR; while some studies indicated pain was present if there was any diagnosis within a given time period, other studies required 2 or more of the same pain diagnosis at least 3 months apart (presumably to match the definition of chronic pain, which requires pain to be present for 3 or more consecutive months).

As summarized for KQ1, studies reported a broad range of pain prevalence estimates, even among those using similar assessment methodology. In general, studies relying on more comprehensive diagnostic assessment methods reported lower pain prevalence estimates than studies using self-report methods of pain assessment. For example, both Seal et al^4^ and Kulas and Rosenheck^39^ extracted EHR data; however, Seal et al required 2 or more instances of the same diagnostic code, more than 90 days apart, whereas Kulas and Rosenheck reported prevalence based on a singular instance of a pain diagnosis. The different prevalence levels of any chronic pain identified were 59% (Seal et al, 2017) and 71% (Kulas and Rosenheck, 2018). Similarly, in studies of head pain, results derived from the EHR,^7,40,45,48,58^ which are based on diagnostic assessment, generally reported lower prevalence levels than studies that reported selfreport data.^42,44,46,50,55^ In 3 different studies using the same self-report measure (the PHQ-15) and same cut-point,^15,59,60^ the authors identified relatively similar pain prevalence levels across studies (eg, range of 7.3% to 9.2% with abdominal/stomach pain).

Figures 3–7 portray the range of prevalence estimates by study and tool for some of the most common types of chronic pain. Where severity or frequency data were available, the estimates in these figures reflect more severe pain (in some cases moderate or higher, in others severe to very severe pain), and more frequent pain (most studies that specified used a cutoff of 15 or more days per month in the case of headaches). Some studies also reported prevalence estimates for multiple time frames of follow-up (such as at 6-month intervals, or pain occurring at less than, versus greater than, 180 days post-injury). Where studies reported multiple time frames, we used the more recent in these figures in order to be more comparable to studies that only examined pain in the past 30 days or 3 months.

Figure 3 Prevalence of general chronic pain in Veterans/Servicemembers with a history of mTBI by study and pain measurement tool

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; EQ-5D-5L=EuroQol Group 5-Dimension 5-Level version

Figure 4 Prevalence of head pain in Veterans/Servicemembers with a history of mTBI by study and pain measurement tool

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; HIT-6=6-Item Headache Impact Test; NSI=Neurobehavioral Symptom Inventory; PDHRA=Post-Deployment Health Re-Assessment; PHQ-15=15-item Patient Health Questionnaire

Figure 5 Prevalence of back pain in Veterans/Servicemembers with a history of mTBI by study and pain measurement tool

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; PDHRA=Post-Deployment Health Re-Assessment; PHQ-15=15-item Patient Health Questionnaire

Figure 6 Prevalence of neck pain in Veterans/Servicemembers with a history of mTBI by study and pain measurement tool

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record

Figure 7 Prevalence of arm, leg, and/or joint pain in Veterans and Servicemembers with a history of mTBI by study and pain measurement tool

Abbreviations: CTBIE=Comprehensive TBI Evaluation; EHR=Electronic Health Record; PDHRA=Post-Deployment Health Re-Assessment; PHQ-15=15-item Patient Health Questionnaire

## KEY QUESTION 2 What is the risk of suicide in US Veterans or Servicemembers with chronic pain and a history of mTBI?

### Summary of Findings

We found 1 study^7^ that addressed KQ2. It also contributed evidence in KQ1. This study only provided data related to sub-question ‘a.’

a How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with a history of mTBI and chronic pain compare to US Veterans or Servicemembers with no mTBI history and/or no chronic pain?

Pugh and colleagues classified Veterans in the study into a number of phenotypes. The Polytrauma phenotype was defined by consistently high comorbidities of mental health disorders, post-concussive symptoms, and pain throughout the study, and therefore we considered this group to represent Veterans in the study with chronic pain and history of mTBI. A second group of interest was the Moderately Healthy + Decline phenotype, characterized by a worsening of symptoms from years 1 to 5. The comparison group is a moderately healthy group of Veterans with a history of mTBI, characterized by “relatively low probabilities of back pain, other pain, mental health and sensory conditions compared to the base-rate in the population.”^7^ The prevalence of suicide-related behaviors (ie, suicidal ideation/attempt, identified based on ICD-9-CM diagnosis codes) in Veterans with mTBI classified in the Polytrauma phenotype (n=11,333) was 6.1% and in the Moderately Healthy + Decline phenotype (n=17,706) was 6.9%, compared to 2.9% in the moderately healthy group of Veterans with a history of mTBI (n=29,168).^7^ Compared to the phenotype of relatively healthy Veterans, both the Polytrauma and Moderately Healthy + Decline groups had significantly higher odds of SRB (adjusted OR=1.4 and 1.3 respectively; CI not reported quantitatively).^7^ This study also compared the prevalence of suicide-related behaviors between those with and without a history of mTBI (eg, 6.6% versus 2.4%, respectively) but did not likewise directly compare suicide-related behaviors between those with mTBI with and without comorbid pain. This study of the entire population of Post-9/11 VA users defined pain based on ICD diagnosis codes.

## KEY QUESTION 3 What are the benefits and harms of interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI?

### Summary of Findings

Three studies^12-14^ met inclusion criteria and addressed KQ3. All 3 studies were focused on treatment for chronic headaches following mTBI. The studies by Leung et al (2016 and 2018) investigated the efficacy of repetitive transcranial magnetic stimulation (rTMS) in 2 small RCTs (N=29 and 44).^12,13^ Nelson and Esty (2015) conducted a small (N=9) pre-post study to investigate a “brainwave-based intervention” described as “the Flexyx Neurotherapy System (FNS) that involves minute pulses of electromagnetic energy stimulation of brainwave activity.”^14^ Table 7 describes study characteristics of the 3 included studies, including descriptions of the study samples and interventions; Table 8 provides additional study details including descriptions of the pain assessment tools used in these trials and outcomes. All 3 studies examined intervention effects in adult US Veterans, many of whom experienced other comorbidities common among Veterans with mTBI history (eg, PTSD, depression, and cognitive dysfunction). Because of the high RoB ratings and small sample sizes of the included studies, the overall body of evidence was rated as having “insufficient” strength of evidence according to AHRQ EPC methods.

Of note is that no studies were identified that compared the efficacy of chronic pain treatments among those with, versus without, mTBI.

### Detailed Results

Results from the 3 included studies are summarized in Table 8. Briefly, the 2 Leung et al studies (2016 and 2018)^12,13^ reported significantly greater reduction in persistent headaches in the rTMS group compared to the group randomized to the sham treatment condition. Similar results were obtained for debilitating headache exacerbation, with significantly greater reductions observed in the rTMS group compared to the sham group in both studies. Nonsignificant differences in global pain intensity were reported for both rTMS studies. Nelson and Esty (2015) reported a consistent decrease in mean pain scores over time, with a mean BPI-HA score of 7.3 (SD=1.2) decreasing to 2.9 (SD=2.6) after 20 FNS (neurotherapy) sessions for “worst pain past week” and a mean BPI-HA score of 4.6 (SD=1.6) decreasing to 1.4 (SD=1.2) after 20 sessions for “average pain past week.”^14^

#### Risk of Bias

Using the Cochrane Risk-of-Bias 2.0 criteria^33^ for RCTs and the Risk of Bias in Non-randomized Studies – of Interventions (ROBINS-I)^34^ for non-randomized intervention studies, we conducted a formal rating of the risk of bias (RoB) of the 3 included treatment studies (see Appendix C, Table 10 for full criteria). The Leung RCTs^12,13^ reported similar methods, though the study published earlier (2016) did not report adequate information on randomization, whereas the 2018 publication reported adequate randomization methods. Neither study reported adequate detail on attrition after consent, and the 2018 study reported that only 29 out of 44 consented participants completed the study and were included in analyses. A notable strength, however, was the reliance on a well-designed and implemented sham control condition in these 2 trials, as well as similar baseline characteristics of treatment and control groups. The study by Nelson and colleagues^14^ provides less robust evidence primarily due to its reliance on a pre-post (uncontrolled) study design and the very small (N=9) sample size. Studies failed to provide adequate detail to assess RoB in numerous domains (eg, randomization, masking, attrition, fidelity). Overall, these 3 studies were all rated as having high RoB. Risk of bias ratings by domain are shown in Table 9.

According to AHRQ methods,^37,38^ we considered study limitations, directness, consistency, precision, reporting bias, dose-response association, and plausible confounding that would decrease the observed effect, strength of association, and applicability to classify the strength of evidence for KQ3 outcomes. While all 3 studies investigated the population of interest, high RoB in combination with the very small number of studies (two from the same research team) and small sample sizes of included studies resulted in a strength of evidence rating of “insufficient” according to AHRQ EPC methods. The “insufficient” rating was based on the following AHRQ criteria: unable to estimate an effect, or no confidence in the estimate of effect for this outcome. The body of evidence has unacceptable deficiencies, precluding reaching a conclusion.

#### KQ3a Do the benefits or harms differ by mTBI etiology, type of chronic pain, mental health comorbidities, intervention setting, and demographics?

Due to the small number of pain trials on limited populations, generalizations about whether benefits and harms differ by mTBI etiology, type of chronic pain, mental health comorbidities, intervention setting, and demographics were not possible.

#### KQ3b How is pain assessed in clinical trials for comorbid chronic pain and history of mTBI in Veterans and Servicemembers?

Table 8 lists measures used to assess pain in clinical trials. Two of the 3 studies examined persistent headaches and debilitating headaches based on headache diaries using numeric rating scales (NRS).^12,13^ These unvalidated headache pain assessments were both based on composite scores of average presence, duration, and intensity. All 3 studies also examined changes on the standardized Brief Pain Inventory (BPI), a validated self-report measure of global pain.

Table 7 Characteristics of studies of interventions for headaches in participants with a history of mTBI Study

Study design Intervention Total N | Selection criteria | mTBI definition and participant characteristics | Intervention | Comparator | Demographics
Leung, 2016^12^; RCT; N=24; (but 5 participants dropped out from the study prior to intervention and were not included in analyses). | US Veterans; age 18–80; history of mTBI; diagnosed ICDH-2 posttraumatic headache; average chronic persistent daily (24/7) headache intensity>30 on 0–100 M-VAS at screening; and average pain intensity>3/10 on NRS reported in the headache diary (between visits 1–2) Also: No prior experience of TMS treatment; no history of daily persistent headache prior to the mTBI incidence. | Head trauma with: either no LOC, or LOC<30 min duration; GCS score ≥13; symptoms and/or signs diagnostic of concussion. | N=12; Three neuronavigation -guided rTMS study treatments with intertreatment interval at least 24 hours or no more than 72 hours apart were administered to the patients within 1 week. | N=12; Sham rTMS | Reported by treatment group; rTMS: Age: 41.2±14.0 yrs.; Female: 2/12 (8.3%).; Sham: Age: 41.4±11.6 yrs.; Female: 1/12 (16.7%).; Mental health comorbidities: PTSD, depression, cognitive dysfunction.
Leung, 2018^13^; RCT; N=29 (but 15 participants dropped out from the study prior to intervention and were not included in analyses) | US Veterans; age 18–65; history of mTBI; diagnosed ICDH-2 posttraumatic headache; average chronic persistent daily (24/7) headache intensity>30 on 0–100 M-VAS at screening; and average pain intensity>3/10 on NRS reported in the headache diary (between visits 1–2) Also: No prior experience of TMS treatment; no history of daily persistent headache prior to the mTBI incidence. | Head trauma with: either no LOC, or LOC<30 min duration; GCS score ≥13; symptoms and/or signs diagnostic of concussion.; Based on published criteria from the 1993 American Congress of Rehabilitation Medicine, and recent DoD recommendation. | N=14; rTMS: at the left prefrontal cortex delivered at 10 Hz, 80% of resting motor threshold and 2000 pulses per session.; 4 sessions at>24 and<72 hours apart | N=15; Sham rTMS | Age: 34.1±7.9 yrs.; Female: 6/29 (20.7%).; Mental health comorbidities: depression, PTSD, cognitive dysfunction.
Nelson, 2015^14^; Pre-post; N=9 | US Veterans with wartime deployments in Afghanistan and/or Iraq; experienced service-connected TBI; other criteria NR. | Majority experienced some LOC (range: a few seconds to a number of minutes); 1 reported having experienced only 1 concussion, the others reported having experienced multiple (typically “many” or “too many to count”), including exposures to explosive blasts. | N=9; FNS: Brainwave-based biofeedback. Involves subtle, minute pulses of EM stimulation computer-adjusted based on EEG feedback. Total of 4 s of EM stimulation spaced over 4 minutes.; 2–3 sessions/week until 20 sessions were completed. | No comparator | Age: 37.3±12.6 yrs (range: 25–64). Time from end of most recent deployment to 1^st^ treatment: 6–103 months (median=46). Taking ≥1 Rx: 7/9 (range=1–7; median=2).; Mental health comorbidities: PTSD (majority of participants); depressive disorders (3 participants).

Abbreviations: DoD=Department of Defense; EEG=Electroencephalogram; EM=electromagnetic energy; FNS=Flexyx Neurotherapy System; GCS=Glasgow Coma Scale; ICDH-2=International Classification of Headache Disorders 2^nd^ Edition; LOC=Loss of consciousness; mTBI=mild traumatic brain injury; M-VAS=Mechanical Visual Analog Scale; NR=Not reported; NRS=Numerical rating scale; PTSD=posttraumatic stress disorder; RCT=randomized controlled trial; rTMS=Repetitive transcranial magnetic stimulation; Rx=prescription medication; TBI=traumatic brain injury; TMS=transcranial magnetic stimulation

Table 8 Findings of studies of interventions for headaches in participants with a history of mTBI

Study design; T vs C; N (T vs C) | Headache definition | Findings | | Risk of Bias
Study design; T vs C; N (T vs C) | Headache definition | Headache pain | Harms | Risk of Bias
Leung, 2016^12^; RCT; rTMS vs sham 12 vs 12 | Persistent headaches: Betweenvisit persistent headache severity averaged (sum of headache rating score/number of days) from daily headache diary.; Debilitating headache exacerbation: composite score generated by multiplying average duration (hours/episode) of headache exacerbation by average frequency (episodes/day) and average intensity (NRS); Global Pain Intensity: BPI assessed baseline level of overall pain (total score divided by a factor of 4), the degree of headache relief (%) from the medication, and overall degree of interference (total score divided by 7) of pain on daily functions. | Persistent headaches: ANOVA (Visit × Treatment): (p=0.06; F=3.93; df=1) of treatment by time interaction. rTMS group had significantly (p=0.041; F=4.73; df=1) higher percentage of persistent headache intensity reduction than the sham group at 1-week posttreatment. A significantly (p=0.035; chi-square=4.44, df=1) higher percentage of rTMS participants (58.3%) demonstrated at least 50% headache reduction than the SHAM group participants (16.6%) at 1-week posttreatment.; Debilitating headache exacerbation: Debilitating headache exacerbation was significantly (p=0.017, F=6.61; df=1.22) reduced in the rTMS group at 4-weeks posttreatment compared to the sham group.; Global Pain Intensity: Visit and treatment interaction for global pain intensity was nonsignificant. | One participant had mild scalp discomfort, no other AEs reported. | High
Leung, 2018^13^; RCT; rTMS vs sham 14 vs 15 | Persistent headaches: Between-visit persistent headache severity=averaged (sum of headache NRS score/number of days) from daily headache diary.; Debilitating headache exacerbation: Composite score generated by multiplying average duration (hours/episode) of headache exacerbation by average frequency (episodes/day) and average intensity (NRS); Global Pain Intensity: BPI assessed baseline level of overall pain (total score divided by a factor of 4), the degree of headache relief (%) from the medication, and overall degree of interference (total score divided by 7) of pain on daily functions. | Persistent Headaches: Two-factor (visit x treatment) ANOVA indicated an overall interaction for average daily persistent headache intensity (F=11.63, DF=1, p=0.002).Significant difference between groups at 1-week (F=21.75, p<0.0001) and 4-weeks (F=11.56, p=0.002) posttreatment. At 4-weeks posttreatment, 57% of the rTMS group no longer experienced persistent headaches compared to 20% of the sham group (F=6.76, p=0.009).; Debilitating Headache: Non-significant difference for debilitating headache composite scores (F=3.71, p=0.062). rTMS group decreased 55.1% (SD=29%) at 1 week and 58.4% (SD=24.5%) at 4 weeks posttreatment whereas sham group decreased 1.7% (SD=41.2%) and 9.5% (SD=60.0%) at 1 week and 4 weeks post-treatment. Debilitating headache duration (F=4.5, p=0.044) and debilitating HA frequency (F=5.57, p=0.026) had improvements in the rTMS vs sham groups. Global Pain Intensity: No significant interaction between visit and treatment on BPI pain interference. | No AEs reported: “Aside from a transient elevation of Perservations score without an overall significant treatment 3 visit interaction or behavioral correlation in the REAL group at post-treatment one-week assessment, the study cohort reported no other side effects.” | High
Nelson, 2015^14^; Pre-post; FNS; N=9 | BPI was modified to indicate 0–10 numeric ratings for pain intensity of headaches in the past week (0=no pain, 10=pain as bad as you can imagine), including worst headache pain and average headache pain. BPI completed at the beginning of treatment and then at sessions 5, 10, 15, and 20 (end of treatment) | Worst pain in past week: t(8)=5.43, p=0.001 (results reported for baseline to end of treatment; means and SDs reported in study for multiple timepoints); Average pain in past week: t(8)=5.86, p<0.001 (results reported for baseline to end of treatment; means and SDs reported in study for multiple timepoints) | “…a few (rarely) reported minor intensifications of their typical symptoms following a treatment session, which was then followed by a more marked reduction in symptom intensity.” | High

Abbreviations: AE=Adverse event; ANOVA=Analysis of variance; BPI=Brief Pain Inventory; C=Comparator; df=degrees of freedom; NRS=Numeric Rating Scale; p=p-value; rTMS=Repetitive transcranial magnetic stimulation; SD=Standard deviation; T=Treatment

Table 9 Risk of bias in trials of interventions for chronic pain in Veterans with a history of mTBI

Study | Intervention vs comparator | Randomization process | Deviations from intended interventions | Missing outcome data | Measurement of the outcome | Selection of the reported result | Overall Bias | Comment
Leung, 2016^12^ | rTMS vs Sham rTMS | High | Some concerns | High | Some concerns | Low | High | Little information about randomization. Masking of providers and assessors was unclear. Analyzed completers only and high attrition. Statistically underpowered.
Leung, 2018^13^ | rTMS vs Sham rTMS | Low | Some concerns | High | Some concerns | Low | High | Masking of providers and assessors was unclear. Analyzed completers only and high attrition. Statistically underpowered.

Abbreviations: rTMS=Repetitive transcranial magnetic stimulation