# METHODS

## TOPIC DEVELOPMENT

This topic was nominated by the VHA Committee on the Care of Veterans with TBI. The scope was refined through a process that included a preliminary review of published peer-reviewed literature and consultations with our operational partners and a technical expert panel (TEP). Our approach was guided by a conceptual framework developed in consultation with our operational partners and TEP (Figure 1. Analytic Framework).

The Key Questions (KQs) for this systematic review were:

KQ1: What is the prevalence of chronic pain in US Veterans or Servicemembers with a history of mTBI?
  a. What are the most common types of chronic pain in US Veterans or Servicemembers with a history of mTBI?
  b. Do the prevalence or types of chronic pain experienced by US Veterans or Servicemembers with a history of mTBI differ by mTBI etiology?
  c. How do estimates of the prevalence of chronic pain and mTBI in US Veterans or Servicemembers differ according to pain measurement methods or definitions?
KQ2: What is the risk of suicide in US Veterans or Servicemembers with chronic pain and a history of mTBI?
  a. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with a history of mTBI and chronic pain compare to US Veterans or Servicemembers with no mTBI history and/or no chronic pain?
  b. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and history of mTBI compare to civilians with chronic pain and history of mTBI?
  c. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and a history of mTBI vary depending on mTBI etiology?
  d. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and a history of mTBI vary depending on prescription opioid use or opioid use disorder?
KQ3: What are the benefits and harms of interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI?
  a. Do the benefits or harms differ by mTBI etiology, type of chronic pain, mental health comorbidities, intervention setting, and demographics?
  b. How is pain assessed in clinical trials for comorbid chronic pain and history of mTBI in Veterans and Servicemembers?

Figure 1 Analytic Framework

Abbreviations: KQ=Key Question; mTBI=Mild traumatic brain injury; QOL=Quality of Life

## SEARCH STRATEGY

Search strategies were developed in consultation with a research librarian and were peer reviewed by a second research librarian using the instrument for Peer Review of Search Strategies (PRESS).^31^ We conducted a review of the literature by systematically searching, reviewing, and analyzing the scientific evidence as it pertains to the research questions. To identify relevant studies, we searched Ovid Medline; Ovid EBM Reviews: Cochrane Central Register of Controlled Trials, Cochrane Database of Systematic Reviews; Ovid PsycINFO; CINAHL; Scopus (conference abstracts only); Google Scholar; and Epistemonikos. We searched all available years of publication from database inception (1946 for Ovid MEDLINE®) through February 7, 2020 (March 4, 2020 for Medline). In the Medline database, we were able to further limit the population with search terms to identify Veterans and/or Servicemembers, and we also conducted a supplementary search with Veteran/Servicemember terms in PsycINFO. We reviewed the bibliographies of relevant articles and contacted experts to identify additional studies. To identify in-progress or unpublished studies, we searched ClinicalTrials.gov, and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP; See Appendix A for full search strategies).

## STUDY SELECTION

Criteria for population, interventions, comparators, outcomes, timing, and setting (PICOTS) were developed in collaboration with our operational partners and TEP (see Table 1). Two investigators independently reviewed the first 42% of titles and abstracts for relevance in order to establish consistency in application of inclusion and exclusion criteria. The remaining titles and abstracts did not contain relevant keywords and were assessed for inclusion by 1 reviewer. Two reviewers then independently assessed the full text of all citations included at the abstract screening phase. All discordant results were resolved through consensus or consultation with a third reviewer. Articles meeting eligibility criteria were included for data abstraction.

For Key Questions 1 and 2, we included primary studies reporting chronic pain prevalence estimates in US Veterans and/or SMs with a history of mTBI. For Key Question 3, we included randomized and non-randomized controlled trials on interventions for chronic pain in Veterans and/or SMs with a history of mTBI from any country. Cohort, prospective, and retrospective studies were also includable for KQ3. Chronic pain was defined as pain lasting or recurring for more than 3 months.^1^ We considered any pain measure that was not clearly described as measuring acute pain to be chronic pain (eg, pain over last 30 days, headaches, etc), along with proxies for chronic pain such as diagnosis codes in healthcare records, analgesic medication use, and conditions usually accompanied by chronic pain (eg, arthritis). We included prevalence estimates for these definitions of chronic pain from any study population that was defined as having a history of mTBI, granted that a clear definition of mTBI was provided. For this report, mild TBI was defined using the VA and Department of Defense common definition of an external force to the head followed by immediate neurological symptoms as indicated by ≤30 minutes of loss of consciousness, 0–1 days of posttraumatic amnesia, or up to 24 hours of altered mental status; individuals had to have normal structural imaging, if completed.^2^ We excluded studies that reported results for a mixed TBI population (mild plus moderate and/or severe) based on the definition of mTBI (See Table 1 and Appendix B for details). Citation lists of included systematic reviews were reviewed for relevant studies. For each key question of interest, we used a “best evidence” approach to guide additional study design criteria depending on the question under consideration and the literature available.^32^

Table 1 PICOTS by Key Question

Key Questions: | KQ1: What is the prevalence of chronic pain in US Veterans or Servicemembers with a history of mTBI?; a. What are the most common types of chronic pain in US Veterans or Servicemembers with a history of mTBI?; b. Do the prevalence or types of chronic pain experienced by US Veterans or Servicemembers with a history of mTBI differ by mTBI etiology?; c. How do estimates of the prevalence of chronic pain and mTBI in US Veterans or Servicemembers differ according to pain measurement methods or definitions? | KQ2: What is the risk of suicide in US Veterans or Servicemembers with chronic pain and a history of mTBI?; a. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with a history of mTBI and chronic pain compare to US Veterans or Servicemembers with no mTBI history and/or no chronic pain?; b. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and history of mTBI compare to civilians with chronic pain and history of mTBI?; c. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and a history of mTBI vary depending on mTBI etiology?; d. How does the prevalence of suicide-related outcomes in US Veterans or Servicemembers with chronic pain and a history of mTBI vary depending on prescription opioid use or opioid use disorder? | KQ3: What are the benefits and harms of interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI?; a. Do the benefits or harms differ by mTBI etiology, type of chronic pain, mental health comorbidities, intervention setting, and demographics?; b. How is pain assessed in clinical trials for comorbid chronic pain and history of mTBI in Veterans and Servicemembers?
Population | US Veterans or Servicemembers with mTBI and chronic pain or headaches; studies reporting a mixed sample of mild and moderate/severe TBI will be excluded if mTBI results are not reported separately | | Veterans or Servicemembers from any country with mTBI and chronic pain or headaches; studies reporting a mixed sample of mild and moderate/severe TBI will be excluded if mTBI results are not reported separately
Intervention | NA | | Pharmacologic, nonpharmacologic, and complementary and integrative health interventions
Comparator | mTBI injury type, direct comparisons to those with no mTBI history and/or no chronic pain, direct comparisons of US Veterans or Servicemembers and civilians | | Placebo, active comparator, usual care, wait-list control, pre-post
Outcome | Prevalence, demographics, chronic pain types | Suicide-related outcomes (including suicide, suicidal ideation/intent/plan, and suicidal self-directed harm) | Benefits: Intermediate and patient outcomes, utilization (eg, reduced pain, mental health diagnosis/symptoms, opioid use; better QOL, functioning, treatment adherence) Harms: AEs, SAEs, withdrawals due to AEs
Timing | Any
Setting | United States | | Any
Study Design | Primary studies that include frequencies; Systematic reviews^*^. Exclude: Case studies/reports, non-systematic reviews, modeling studies. | | RCT, NRCT, cohort, prospective, retrospective studies; Systematic reviews^*^. Exclude: Case studies/reports, non-systematic reviews, modeling studies.

* Reference lists from relevant systematic reviews were reviewed.

Abbreviations: AE=adverse event; mTBI=mild traumatic brain injury; NA=not applicable; NRCT=non-randomized controlled trial; PICOTS=population, interventions, comparators, timing, setting, and study design; QOL=quality of life; RCT=randomized controlled trial; SAE=severe adverse event; US=United States

## DATA ABSTRACTION

Data from studies meeting inclusion criteria were abstracted by 1 reviewer and confirmed by at least 1 additional reviewer. From each study, we abstracted the following a priori-defined categories of data when reported in the publications: study design, sample size, setting, population characteristics (including demographics, military service characteristics, and mental health comorbidities where available), definitions and operationalizations of mTBI and pain, participant inclusion and exclusion criteria, and results. In studies where comparison data were presented for groups without mTBI, these pain prevalence estimates were also abstracted. For intervention studies, we also abstracted intervention and comparator characteristics including dosage, timing, and duration of treatment, duration of follow-up, adjunctive interventions (if applicable), and behavioral and health outcomes, as well as relevant harms.

## QUALITY ASSESSMENT

Two reviewers independently assessed the methodological quality of each study using established methods for each study design. To assess risk of bias (RoB), we used the Cochrane Risk-of-Bias 2.0 criteria^33^ for RCTs and the Risk of Bias in Non-randomized Studies – of Interventions (ROBINS-I)^34^ for non-randomized intervention studies. We adapted the Newcastle-Ottawa Scale^35^ supplemented with another critical appraisal tool for prevalence studies^36^ for all other study designs (see Appendix C). Ratings of quality were specific to the outcome of interest (ie, prevalence of chronic pain or suicide for KQs 1 & 2 and treatment of chronic pain in KQ3). Disagreements were resolved by consensus of a third reviewer and/or the entire review team.

## DATA SYNTHESIS

We qualitatively synthesized the evidence for all key questions and presented the findings in tables. We were not able to conduct quantitative meta-analyses for prevalence estimates because of the heterogeneity of study populations and chronic pain and mTBI measures across studies. Neither were we able to combine intervention studies due to the small number of studies and heterogeneity of interventions and outcomes.

## RATING THE BODY OF EVIDENCE

We assessed the overall strength of evidence (SOE) for KQ3 outcomes using a method developed for the Agency for Healthcare Research and Quality’s (AHRQ) Evidence-based Practice Centers (EPCs).^37^ The AHRQ EPC method considers study limitations, directness, consistency, precision, and reporting bias to classify the strength of evidence for individual outcomes independently for randomized controlled trials (RCTs) and observational studies, with supplemental domains of dose-response association, plausible confounding that would decrease the observed effect and strength of association, as well as separate guidance for applicability.^38^ Ratings were based on the following criteria:

- High: Very confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has few or no deficiencies, the findings are stable, and another study would not change the conclusions.
- Moderate: Moderately confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has some deficiencies and the findings are likely to be stable, but some doubt remains.
- Low: Limited confidence that the estimate of effect lies close to the true effect for this outcome. The body of evidence has major or numerous deficiencies (or both). Additional evidence is needed before concluding either that the findings are stable or that the estimate of effect is close to the true effect.
- Insufficient: No evidence, unable to estimate an effect, or no confidence in the estimate of effect for this outcome. No evidence is available, or the body of evidence has unacceptable deficiencies, precluding reaching a conclusion.