# INTRODUCTION

The post-9/11 military operations in and around Afghanistan and Iraq (Operations Enduring Freedom, Iraqi Freedom, and New Dawn, or OEF/OIF/OND) have served to highlight the high prevalence of mild traumatic brain injury (mTBI) in Servicemembers (SMs) and Veterans, often referred to as the “signature injury” of these conflicts.^15^ Approximately 413,000 SMs have experienced a traumatic brain injury (TBI) since the year 2000, and over 80% of those were classified as mild in severity.^16^

Mild TBI often resolves completely and quickly, without the need for much or any intervention. However, up to one-third of individuals who experience an mTBI have a longer and/or more severe symptom course.^17,18^ It is not clear why some individuals experience long-term sequelae from mTBI events while others experience complete resolution.^19^ Among SMs and Veterans in particular, it is also unclear whether symptoms and sequelae that are attributed to mTBI are due to the mTBI itself or, rather, are physical and mental health outcomes related to the same exposures (ie, related to combat) that led to the mTBI.

Regardless of the source, it is important to provide rehabilitative services to individuals with a history of mTBI to maximize functional outcomes.^19^ To meet Veterans’ needs, the Department of Veterans Affairs (VA) Veterans Health Administration (VHA) developed a comprehensive system of care to ensure that those exposed to mTBI and who may be experiencing long-term sequelae are referred for appropriate services. This TBI/Polytrauma System of Care involves a brief screen, used universally with nearly all OEF/OIF/OND Veterans, to detect potential history of mTBI plus current symptoms that may be related; a follow-up clinical evaluation (the Comprehensive TBI Evaluation, or CTBIE) with a specialist to confirm whether symptoms are or are not related to mTBI, and to provide referrals for related care needs; and a network of polytrauma providers and clinics to ensure Veterans’ TBI-related needs are met.^20^ The TBI/Polytrauma System of Care has been lauded for ensuring that Veterans with mTBI-related symptoms and sequelae are identified and receive care that maximizes functioning and quality of life.^21^ However, the screening and evaluation program has also been criticized for causing inflated symptom reporting, reduced recovery expectations, and leading to other iatrogenic effects among Veterans who may not otherwise experience long-term effects of mTBI.^22,23^

Common sequelae and health conditions that are associated with mTBI include mental health concerns such as posttraumatic stress disorder (PTSD) and depression, cognitive problems, sensory sensitivity, and chronic pain,^17,18,24^ which are often associated with significant functional limitations. Due to the common co-occurrence of mTBI, PTSD, and chronic pain among SMs and Veterans, clinicians and researchers have described these comorbidities as the polytrauma clinical triad.^25^ The extent to which these comorbidities interact to further increase the risk of functional limitations or other adverse outcomes beyond mTBI history alone is unknown, but the number of patients meeting the polytrauma clinical triad definition, and the potential for poor outcomes among these individuals, warrants close attention. While some recent clinical intervention research has targeted comorbid mTBI and PTSD (eg, Pagulayan et al, 2017^26^), there is very limited research on interventions specifically targeting chronic pain among individuals with a history of mTBI (eg, Irvine, 2018^27^) or targeting the triad of conditions.

The rate of suicide among military SMs and Veterans is higher than among the general US population and continues to increase annually.^28^ Although the reasons for increased risk of suicide among SMs and Veterans, relative to others, are not well understood, both mTBI and pain have been identified as risk factors in both Veteran and non-Veteran populations.^10,11,29,30^ Whether or not comorbid mTBI and pain would interact to increase risk of suicide beyond the risk associated with either condition alone is unknown, but it stands to reason that SMs and Veterans with a history of both mTBI and pain are a potentially high-risk population. Understanding this risk and developing therapies or other interventions that can reduce it, in this population or among SMs and Veterans more generally, is critical.

Because these complexities and additional clinical complications may be present when mTBI and pain are co-occurring, there is a need to better understand both the epidemiology of these conditions and their potential impact on risk of suicide and suicide-related behaviors. There is also a need for a comprehensive understanding of the effectiveness of intervention research targeting chronic pain among individuals with a history of mTBI. The purpose of this systematic review is to address these epidemiologic and clinical research questions by identifying and synthesizing existing literature on mTBI and chronic pain, highlighting research gaps and future research needs, as well as describing evidence specifically related and relevant to Veterans and SMs.