# EXECUTIVE SUMMARY

## AIM

We conducted a systematic review to synthesize the existing literature on the prevalence of chronic pain in Veterans and Servicemembers (SMs) with a history of mild traumatic brain injury (mTBI), the risk of suicide in this population, and the benefits and harms of interventions to treat chronic pain in this population.

## METHODS

We searched electronic databases (Ovid Medline; Ovid EBM Reviews: Cochrane Central Register of Controlled Trials, Cochrane Database of Systematic Reviews; Ovid PsycINFO; CINAHL; Scopus; Google Scholar; and Epistemonikos), clinical trial registries, and reference lists from database inception through February 7, 2020 for studies providing prevalence estimates of chronic pain in US Veterans or SMs with a history of mTBI, reporting estimates of suicide risk among US Veterans or SMs with a history of mTBI and chronic pain, or examining treatment interventions for chronic pain in Veterans or SMs with a history of mTBI from any country. For intervention studies, we included only randomized and non-randomized controlled trials.

Chronic pain is commonly defined as pain lasting or recurring for more than 3 months,]^1^ though definitions vary across published studies. In order to provide a comprehensive overview of this body of literature, we considered any pain measure that was not clearly described as measuring acute pain to be chronic pain (eg, pain over past 30 days, headaches, etc), along with proxies for measures of chronic pain such as diagnosis codes in healthcare records, analgesic medication use, and conditions usually accompanied by chronic pain (eg, arthritis). We included prevalence estimates for these definitions of chronic pain from any US Veteran or SM study population that was explicitly defined as having a history of mTBI, distinct from TBI of greater severity. Mild TBI was defined as an external force to the head followed by ≤30 minutes of loss of consciousness, 0–1 days of posttraumatic amnesia, or up to 24 hours of altered mental status, along with normal structural imaging if completed.^2^ We excluded studies that reported results for populations with mixed TBI severity (eg, mild plus moderate and/or severe TBI). For each key question of interest, we used a “best evidence” approach to guide additional study design criteria depending on the question under consideration and the literature available.

For all studies we abstracted study design, sample size, setting, population characteristics, participant inclusion and exclusion criteria, definitions/operationalizations of key variables, and results. If data were presented for non-mTBI comparison groups, these were also abstracted. For intervention studies, we also abstracted intervention and comparator characteristics including dosage, timing, and duration of treatment, duration of follow-up, adjunctive interventions (if applicable), and behavioral and health outcomes, as well as relevant harms. Two reviewers independently assessed the methodological quality of each study using established methods for each study design. Strength of evidence for intervention studies was determined by consensus.

## RESULTS

We identified 27 articles (representing 26 studies) reporting chronic pain prevalence estimates in US Veterans and SMs with a history of mTBI, 1 study examining suicide outcomes in US Veterans and SMs with a history of mTBI, and 3 studies examining interventions for the treatment of chronic pain in Veterans and SMs with a history of mTBI from any country.

### Key Question 1 What is the prevalence of chronic pain in US Veterans or Servicemembers with a history of mTBI?

Included prevalence studies describe a wide range of chronic pain types, with the most common being head pain (ie, headaches or migraines, 23 studies), followed by back pain (10 studies), and arm, leg, and/or joint pain (9 studies). Four articles reported the use of pain medication (eg, analgesics including opioids) as an indicator of chronic pain (see Figure i). Across studies there was substantial heterogeneity in sample size (ie, 40 to 102,055 Veterans or SMs with history of mTBI), population (eg, Veterans, SMs, or both; era of service; geographic region; comorbid conditions; and combat exposure), time since mTBI, and length of follow-up, as well as the methods used to identify, define, and operationalize both mTBI and chronic pain.

Figure i Number of studies reporting prevalence of chronic pain in Veterans/Servicemembers with histoy of mTBI, by pain type

Note. Some studies reported multiple pain types.

Across these studies, the prevalence of chronic pain among Veterans and SMs varied widely but, overall, was high. As expected in this population, prevalence estimates of head pain and chronic pain generally were higher than estimates of other specific chronic pain conditions (eg, chest pain, abdominal/stomach pain). However, across studies, there were wide ranges of prevalence estimates for each pain type, likely due to the varying study designs, target populations or samples, pain definitions, operationalization of key variables, and pain ascertainment periods (see Figure ii). This heterogeneity across studies limits the conclusions that can be drawn about the frequency of pain or the most common pain types among Veterans and SMs who have experienced mTBI. However, when studies presented pain prevalence data for comparison groups without mTBI, they were consistently lower across all pain types.

Figure ii Range of chronic pain prevalence estimates by pain type across studies

Although the wide variation in estimates is not surprising given the heterogeneity across studies, these findings, or rather the lack of concrete findings, highlight a need to establish and implement consistent methods to assess pain conditions that are prevalent in US Veteran and SM populations. Studies are needed to assess the prevalence of chronic pain among all US Veterans and SMs with a history of mTBI (rather than, for example, treatment-seeking Veterans specifically) and to compare the prevalence levels of pain types by important Veteran and SM characteristics, including service history, physical and mental health comorbidities, and healthcare utilization patterns. Additionally, despite being beyond the scope of this review, we noted that few studies compared pain prevalence between those with and without mTBI and, thus, it remains unclear how pain conditions are associated with mTBI (ie, whether they tend to be more commonly diagnosed among treatment-seeking samples, whether they are a result of the mTBI itself, or whether they are a result of the same characteristics and exposures that led to mTBI). To answer these questions and maximize usefulness of the evidence, studies that randomly sample Veterans and SMs, follow them over time, and use established and consistent definitions and operationalizations of mTBI and pain are needed.

Similarly, although we found well-conducted studies of treatment-seeking samples of Veterans and SMs that reported on chronic pain among those with mTBI, these studies by nature relied on selective (ie, non-random) samples and/or proxy measures of mTBI and pain such as International Classification of Diseases (ICD) diagnosis codes. To better understand the prevalence of chronic pain conditions and, in particular, to anticipate treatment needs among Veterans and SMs who utilize the VA or Military Health System, random or otherwise representative samples of individuals with (and, for comparison, without) mTBI should be assessed using established and consistent chronic pain definitions and measures.

For this review, we chose to include studies of chronic pain even if the study did not include a rigorous assessment to determine the chronicity or severity of pain symptoms. For example, we included studies where pain symptoms were assessed only for the past month. While this methodology could result in over-estimation of the prevalence of chronic pain, we opted to include these studies in order to generate a fuller picture of the problem of pain among Veterans and SMs with a history of mTBI. Future research that aims to understand chronic pain in a sample of all Veterans/SMs with mTBI history, or of specified treatment-seeking Veterans/SMs with mTBI history, would benefit from the assessment of pain chronicity (at least 3–6 months) and severity (moderate or higher). There are also recommended strategies for assessing chronic pain using administrative data, such as ICD diagnosis codes, that can improve the accuracy and comparability of prevalence estimates in these types of studies of chronic pain.^3^

For general chronic pain among Veterans with a history of mTBI, we identified a relatively robust prevalence estimate of 59% from Seal et al.^4^ This estimate was derived from a large database of Post-9/11 Veterans who completed a Comprehensive TBI Evaluation (CTBIE) in the VA healthcare system and, thus, represents a relatively large target population. However, Veterans who complete the CTBIE are generally seeking treatment for a variety of post-deployment health symptoms that may or may not be related to mTBI, or pain. The CTBIE is a standardized and templated clinical assessment completed by a specialty provider and includes standardized assessments of pain; however, patients who complete the CTBIE may not need pain-related care (ie, are not bothered by pain). When CTBIE data or pain diagnosis codes are used to estimate chronic pain, as in the case of this study, the true prevalence of chronic pain may be over- or underestimated. Most other studies examining general chronic pain included fewer than 500 participants and used varied methods to identify chronic pain. The only other large study utilized VA electronic health record (EHR) data and reported pain diagnoses in 82% of Veterans with diagnosed mTBI and comorbid posttraumatic stress disorder (PTSD), and 71% among those with mTBI but no PTSD diagnosis. This study identified mTBI and chronic pain by the presence of ICD diagnosis codes in EHR data and may over- (or even under-) estimate their prevalence due to this approach.^3,5^ Studies of pain disability/interference (defined as moderate-to-severe interference in daily functioning) due to chronic pain were fairly consistent, with estimates of 70–75%. Studies of pain severity, based on self-report using Likert-like scales, indicated that roughly half of Veterans and SMs with a history of mTBI reported moderate to severe pain, and studies that examined pain frequency reported that about one-third to one-half experience pain more than 15 days per month.

Head pain such as headaches and migraines was the most studied chronic pain type (23 studies), with prevalence estimates ranging widely from 3% to 98%. Relatively robust (but still widely varied) estimates come from 5 large studies, all of which used EHR or CTBIE data and thus may not represent the true prevalence of head pain across the population of Veterans or SMs with mTBI history. Among these 5 studies, prevalence estimates of headache or migraines from 4 studies of Post-9/11 Veterans with a history of mTBI ranged from 20% to 94% (this latter study reported data from a CTBIE item assessing the presence of any headaches), and 1 study of SMs reported headache prevalence estimate of 15.2%. Prevalence estimates appear to vary by target population (Veteran versus SM; healthcare utilization), time since mTBI, length of follow-up, method of identifying and classifying chronic pain (and mTBI), and data source. Many of the studies examined EHR data that include all Veterans or SMs with mTBI and chronic pain-related ICD codes. Other studies, including those of the large cohort of Veterans who completed the CTBIE, were of treatment-seeking populations, which would be expected to have higher pain prevalence. This difference alone may account for much of the variance between studies. The prevalence estimates of moderate to severe pain, and frequent pain, also varied widely.

Prevalence estimates for back pain were largely consistent, falling between 32% and 44% for SMs in 3 studies using the 15-item Patient Health Questionnaire (PHQ-15), and 13%-15% for upper back and 53%-58% for lower back pain among Veterans who completed the CTBIE. There was wide variation in the prevalence estimates of neck pain in Veterans with a history of mTBI. The 2 largest studies reported prevalence estimates of 6% (VA EHR data) and 23% (CTBIE). With the exception of arthritis (41.1% to 51%), the prevalence estimates of other pain types were relatively low.

Four articles reported on pain medication use which we abstracted as a proxy measure for chronic pain. Of these, 2 relatively small studies specifically looked at opioid medication use for pain. Estimates of prevalence of opioid use among Veterans with a history of mTBI from these studies were 12% and 49%; these differences were likely due to the different data sources, populations, and timing of measurements used in these studies.

Three studies compared the prevalence of chronic pain in Veterans and SMs with a history of mTBI by mTBI etiology. These studies compared chronic pain prevalence among individuals who experienced mTBI from blast versus non-blast sources; no studies were identified that compared pain prevalence levels by other etiologies. Overall, in the 3 studies identified, blast-related mTBI did not appear to be associated with more frequent and more severe pain. However, 1 study reported that, among Veterans who experienced loss of consciousness (LOC) after their mTBI, those with blast-related mTBI had a significantly higher prevalence of head pain than those with non-blast-related mTBI (40% versus 23%). None of the other pain types assessed in this study differed by mTBI etiology. None of the studies examined or compared pain prevalence by location of mTBI, location of co-occurring injuries, or timing of pain onset relative to the mTBI.

Results of studies examining pain assessment methods suggest that different types of pain measures were associated with higher or lower pain prevalence estimates. In addition to pain assessment methods, other aspects of study design likely influenced prevalence estimates as well. For example, studies of specialized clinics designed to treat a particular condition would be expected to have higher rates of that condition (such as in the study by Ruff et al,^6^ of a small sample seen in a polytrauma clinic) than studies examining the prevalence in a broad, full, or “all-comers” population (such as in studies examining all post-deployment Veterans/SMs or identifying pain diagnoses in the EHR).

### Key Question 2 What is the risk of suicide in US Veterans or Servicemembers with chronic pain and a history of mTBI?

We found only a single study examining suicide-related outcomes in US Veterans and SMs with both chronic pain and a history of mTBI. The study used VA EHR data and categorized Veterans with and without a history of mTBI into trajectory groups based on an algorithm using ICD diagnosis codes. As compared to those with relatively low rates of mental health, pain, and other sensory diagnoses during the trajectory development period, Veterans with high mental health, post-concussive symptoms, and pain comorbidities were significantly more likely to have been diagnosed with suicidal ideation or attempt during the follow-up period.^7^ This study compared the prevalence of suicide-related behaviors between those with and without a history of mTBI (eg, 6.6% versus 2.4%, respectively) but did not likewise directly compare suicide-related behaviors between those with mTBI with and without comorbid pain. However, considering the persistently high rates of suicide in Veteran populations,^8,9^ and higher rates of suicide and other causes of mortality among Veterans with a history of mTBI compared to those without,^10,11^ more research of this particularly vulnerable population is needed.

### Key Question 3 What are the benefits and harms of interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI?

Although chronic pain is well established as a common comorbidity among Veterans and SMs with a history of mTBI, we found very few trials of interventions to treat chronic pain in this population, even when searching for studies from any country. The 3 studies that met inclusion criteria were small and provide insufficient-strength evidence supporting the interventions studied (repetitive Transcranial Magnetic Stimulation [rTMS] in 2 RCTs and Flexyx Neurotherapy System [FNS], a type of neurotherapy, in 1 small pre-post trial). All 3 studies targeted chronic headaches, and none assessed nor treated other types of chronic pain.^12-14^ Also notable is that no studies compared the efficacy of chronic pain treatments among those with, versus without, mTBI. This review was limited to chronic pain treatment trials of Veterans and SMs with a history of mTBI from any country because of the unique military-related circumstances (eg, blast exposure) that can contribute to pain in this population. However, due to the very small number of trials specific to this population, future efforts should consider results from pain interventions among broader populations (eg, adult civilians) or Veterans and SMs without a history of mTBI when making treatment, policy, or research scoping decisions.

## CONCLUSION

Chronic pain, particularly head and back pain, is common among US Veterans and SMs with a history of mTBI, as is the use of medications indicative of pain conditions, such as prescription opioids. In studies providing comparisons, pain prevalence estimates are consistently higher among those with, versus without, mTBI history, and for those with comorbid mTBI and PTSD compared to those with mTBI but no PTSD. Based on the existing research, precise estimates of the prevalence of pain conditions, locations, disability/interference, and severity are hampered by heterogeneity in study populations/samples, timing of pain ascertainment relative to individuals’ mTBI history, duration of study follow-up, and methods used to identify, define, and operationalize both mTBI and chronic pain. Additionally, only a single study examined the risk of suicide, and only 3 trials of interventions to treat chronic pain in this complex population were identified. Thus, the prevalence of chronic pain in the general population of US Veterans and SMs, the impact of comorbid pain and mTBI on suicide risk in this population, and the efficacy of pain therapies among those with comorbid mTBI and chronic pain remain largely unknown. Research studies specifically designed with the intent of filling these knowledge gaps are needed to inform current and future service needs for this population. Given the high prevalence of mTBI history in Veterans and SMs, and the importance of meeting the social and clinical needs of this large population, this research is urgent and essential.

## ABBREVIATIONS TABLE

Abbreviation: Definition
AA: African-American
AE: Adverse Event
ANOVA: Analysis of Variance
AOC: Alteration of Consciousness
CA: California
CDC: Centers for Disease Control and Prevention
CDH: Chronic Daily Headaches
CDP-SOT: Computerized Dynamic Posturography Sensory Organization Test
CDSR: Cochrane Database of Systematic Reviews
CENC: Chronic Effects of Neurotrauma Consortium
CI: Confidence Interval
CO: Colorado
CoE: Center of Excellence
CP: Chronic pain
CTBIE: Comprehensive TBI Evaluation
DMDC: Defense Manpower Data Center
DMSS: Defense Medical Surveillance System
DoD: Department of Defense
DVBIC: Defense and Veterans Brain Injury Center
EBM: Evidence-Based Medicine
EEG: Electroencephalogram
EHR: Electronic Health Record
EM: Electromagnetic Energy
ESP: Evidence Synthesis Program
EQ-5D-5L: EuroQol Group 5-Dimension 5-Level version
FH: Frequent Headaches
FL: Florida
FNS: Flexyx Neurotherapy System
FY: Fiscal year
GCS: Glasgow Coma Scale
HI: Hawaii
HIT-6: 6-item Headache Impact Test
ICD: International Classification of Diseases
ICD-9-CM: International Classification of Diseases, Ninth Revision, Clinical Modification
ICDH-2: International Classification of Headache Disorders 2^nd^ edition
ICDH-3: International Classification of Headache Disorders 3^rd^ edition
ISS: Injury Severity Scale
KQ: Key Question
LOC: Loss of Consciousness
MA: Meta-Analysis
MD: Mean Difference
mTBI: Mild Traumatic Brain Injury
MINI: Mini-International Neuropsychiatric Interview
M-VAS: Mechanical Visual Analog Scale
NA: Native American
NC: North Carolina
NR: Not Reported
NRCT: Non-Randomized controlled trial
NRS: Numerical Rating Scale
NS: Not Significant
NSI: Neurobehavioral Symptom Inventory
OEF: Operation Enduring Freedom
OH: Ohio
OIF: Operation Iraqi Freedom
OND: Operation New Dawn
OSU TBI-ID: Ohio State University Traumatic Brain Injury Identification Method
P: P-value
PCE: Potential Concussive Event
PCL-17: 17-item Posttraumatic Stress Disorder Checklist
PDHA: Post-Deployment Health Assessment
PDHRA: Post-Deployment Health Re-Assessment
PHQ-15: 15-item Patient Health Questionnaire
PHQ-9: 9-item Patient Health Questionnaire
PICOTS: Population, Interventions, Comparators, Outcomes, Timing, Setting, and Study Design
PNS: Polytrauma Network Site
PPCS: Persistent Post-Concussive Symptoms
PTA: Posttraumatic Amnesia
pts: Participants
PTSD: Posttraumatic Stress Disorder
QOL: Quality of Life
RCT: Randomized Controlled Trial
RoB: Risk of Bias
RR: Relative Risk
rTMS: Repetitive Transcranial Magnetic Stimulation
Rx: Prescription Medication
SAE: Serious Adverse Event
SD: Standard Deviation
SE: Standard Error
SM: Servicemember
SMD: Standard Mean Difference
SOE: Strength of Evidence
SR: Systematic Review
SRB: Suicide Related Behavior
TBI: Traumatic Brain Injury
TBIMS: Traumatic Brain Injury Model Systems
TEP: Technical Expert Panel
TMS: Transcranial Magnetic Stimulation
TRACTS: Translational Research Center for TBI and Stress Related Disorders
TX: Texas
US: United States
VA: Veterans Affairs; or Virginia
VALOR: Veterans’ After-discharge Longitudinal Registry
VAMC: Veterans Affairs Medical Center
VCU-rCDI: Virginia Commonwealth University retrospective Concussion Diagnostic Interview
VHA: Veterans Health Administration
WRAMC: Walter Reed Army Medical Center