# APPENDIX E PEER REVIEW COMMENTS/AUTHOR RESPONSES

Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | Yes
2 | Yes
3 | Yes
4 | Yes
5 | Yes
6 | Yes
7 | Yes
8 | Yes
9 | Yes
10 | Yes
Is there any indication of bias in our synthesis of the evidence?
1 | No
2 | No
3 | No
4 | No
5 | No
6 | No
7 | Yes - This review had tremendous amount rejection of articles. Would like to see a list of articles that were rejected by a third reviewer, as opposed to those that had 2 reviewers that agreed. | We understand this point. Our search terms were purposely broad to identify all possible papers with data on TBI and pain. This resulted in a large number of irrelevant studies that were excluded upon review of abstracts or full text for reasons such as focusing on moderate/severe rather than mild TBI, or being conducted in civilian samples (i.e., outside of the scope of this review). Inclusion/exclusion determinations were based on dual review and consensus. We now include a table of studies that were excluded after the full text review (Appendix D).
8 | No
9 | No
10 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
1 | No
2 | No
3 | Yes - For awareness and potential mention-study of VHA cohort just published: Amy L. Byers, Yixia Li, Deborah E. Barnes, Karen H. Seal, W. John Boscardin & Kristine Yaffe (2020) A national study of TBI and risk of suicide and unintended death by overdose and firearms, Brain Injury, 34:3, 328–334, DOI: 10.1080/02699052.2019.1701708 31822136 | Thank you. We have cited this new publication in the Introduction and Discussion sections of the report.
4 | No
5 | No
6 | No
7 | No
8 | No
9 | No
10 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report
1 | This is a well-conducted and well-described review. I have only a few minor suggestions. | We appreciate the feedback.
1 | Page 16: The authors have been appropriately inclusive in their selection criteria for studies of chronic pain and have not applied a strict definition of chronic pain; however, I think it would be helpful to provide a standard definition of chronic pain (e.g., IASP, National Pain Strategy) in the introduction. | Thank you for this suggestion. We have added a definition of chronic pain to the Introduction section of the report.
1 | Page 58, lines 23–34: I think it is misleading to describe use of ICD-9/10 codes as “comprehensive diagnostic assessment.” ICD-9/10 do not include a systematic approach to chronic pain, so studies using these codes typically infer the presence of chronic pain from codes that indicate the presence of a symptom (e.g., low back pain), imaging finding (e.g., disc degeneration), or disease (e.g., osteoarthritis) that may or may not be associated with chronic pain. Perhaps the best way to think about most of these codes is as “diagnoses potentially related to chronic pain.” Clinicians often do not code comprehensively, but typically chose codes for reasons related to billing. This could lead to under or over coding. In most cases when chronic pain is present, clinicians have little incentive to add codes for pain-related diagnoses because they add little to the overall complexity of the visit. In some cases, such as when patients have a service-connected condition potentially related to chronic pain, clinicians may code a pain-related diagnosis to spare a patient a copay, even if the condition was briefly discussed and determined not to be bothersome. | Thank you for this information. We agree that ICD diagnosis codes do not necessarily equate to chronic pain and there are circumstances when the use of these codes may increase false positive or false negative rates. We have edited the report to include this as a limitation to the conclusions drawn from studies using ICD codes. Additionally, we have reviewed and edited the report for use of appropriate language, including the suggested “diagnoses potentially related to chronic pain.”
2 | This reviewer appreciates the efforts put forth to produce this review. Methods are clearly articulated and implemented. | We appreciate this feedback.
2 | *May be helpful to clarify that the most robust study - Key Question 1 - CTBIE - findings - are for that specific cohort. The fact that those in this group also had the most comprehensive eval creates further challenges in terms of interpretation. | We agree. We have added additional information about the CTBIE to the Results section, including potential caveats when interpreting findings from these studies.
2 | *The role of co-occurring MH sx could be further integrated throughout. If this is not possible - may be helpful to identify as a limitation. | Though this was outside the scope of Key Question 1, Key Question 2 examined suicide-related outcomes (evidence from 1 study). Key Question 3 examined whether benefits or harms of treatment differed by mental health comorbidities, though due to the small number of studies and participants relevant to this key question, we were unable to generalize about potential impacts of mental health comorbidities. We have noted this as a limitation of our review and recommended it as a future research area in the discussion. We have also included a discussion section highlighting differences in prevalence estimates for individuals with PTSD: “Although we did not find strong evidence suggesting that pain prevalence varied by mTBI etiology, it was clear across studies that, when examined, pain prevalence levels were substantially higher among those with comorbid PTSD. Although the assessment of pain prevalence by comorbid PTSD was not a specified focus of KQ1, the consistency of this finding across studies is noteworthy, particularly given the high prevalence of diagnoses PTSD among those with a history of mTBI. This finding lends further evidence to prior discourse about the “polytrauma clinical triad”^25^ and has implications for the ongoing clinical management of Veterans and SMs with mTBI.”
2 | *In addition, further discussion of multiple pain types and clinical implications would be useful. | We have included a description of pain definitions in the evidence tables to facilitate comparisons across different definitions of pain used in the included studies. Few studies reported the prevalence of participants with multiple pain types; however, where possible, we have added this information to the Results section as well as a description of the clinical implications in the Discussion section.
3 | 1. P4 (line 46) Consider reporting the higher rates of suicide in Veterans with history of mTBI (beyond non-TBI or all Veterans). Given that suicide is VA’s clinician priority, it may be prudent to briefly summarize findings from published, peer-reviewed studies on the prevalence of suicide following TBI. This may serve to highlight it’s importance for this population in light of the lack of studies that met the ESR’s criteria. | We have added text and references to the Executive Summary identifying the higher rates of mortality, and suicide mortality, among Veterans with a history of mTBI. In the full Introduction section, we have added a paragraph describing the findings from past peer-reviewed studies.
3 | 2. The ESR on mTBI and pain could be stronger by mentioning the contributions of other factors, including prevalent medical/mental health comorbidities to pain/symptom chronicity. Along the same lines, the conclusion could be more compelling from a clinical, research and VHA policy perspective if there was brief mention of the impact of co-existing mTBI and pain on (for example) longterm healthcare utilization, functional outcomes and quality of life. | We agree with this recommendation and have added more information on the consideration of comorbidities in the included studies and the potential interplay of comorbidities with chronic pain among those with mTBI. Similarly, we have included a brief reference to likely healthcare utilization, functional outcomes, and quality of life in this patient population.
3 | Very interesting to read and informative ESR. Thank you. | We appreciate this feedback.
4 | This is a very nice review and summary of the literature. I appreciate the authors grouping of the studies and the fact that the summary results were not overstated. I would like to recommend a paragraph in the executive summary that provides a high level overview of the noted gaps in the literature as this would be helpful for future grant applications to reference. There body of the report could include a short discussion of the gaps in the literature and challenges (lack of consistent use of similar outcome measures, impact of co-morbid MH diagnosis and pain prevalence which is already described on page 64, recommendations to include suicide risk assessment in future studies, and need for treatment studies). Overall very nicely done. | Thank you for this suggestion. We have added a paragraph to the executive summary identifying the gaps and challenges and have now better highlighted this throughout the report, including additional text in the Discussion section.
5 | P 2 line 49 figure 2 Insert comment/analytics about the reasons for the wide range of reported prevalence’s and how this affects report utility. | We have added text describing the likely reasons for heterogeneity in prevalence estimates as well as the effect on report utility.
6 | As expected, this is a critical, comprehensive, unbiased, and important review of the scientific literature regarding co-occurring TBI and pain that identifies both the limited available high quality literature and the lack of clinically important associations. I have no significant recommended edits or additions. | Thank you. We agree this review highlights gaps in the current literature and important next-steps for addressing chronic pain among Veteran and military populations with a history of mTBI.
7 | Would like a list of publications that required a tie-breaker vote. | We now include an appendix (Appendix D) with the list of studies excluded after full text review. We used dual review and team consensus to determine study eligibility.
8 | This Evidence Synthesis Program review is both timely and significant in light of growing attention to chronic pain as a significant public health and clinical problem, particularly for Veterans and Military Service Members (SMs).; Overall, the report is very well done. Prespecified key questions were addressed appropriately via strong and well-supported review and thoughtful and comprehensive discussion of the findings. Although there are numerous concerns about the reliability and reproducibility of the findings, the authors have generally acknowledged serious limitations of the existing literature and the approach to answering the questions. The methods employed in the search process are state-of-the-art and encourage confidence that the literature relevant to addressing key questions was identified and considered. The description of individual studies identified in the search is a strength of the report. Tables are particularly valuable in capturing key features of individual studies. While the authors’ efforts to draw conclusions based on a summary of these findings given the heterogeneity of the studies and their approaches is admirable, summary statements and conclusions based on this review are likely to be less than optimally useful in informing operational partner interests in identifying actionable recommendations for improving the care of Veterans and SMs with co-occurring mTBI and chronic pain. | We appreciate this feedback.
8 | Numerous concerns and recommendations for improving the quality of the report, most of which already acknowledged by the authors, can be cited.; In the Executive Summary, care is taken to explicate how “chronic pain” was ascertained. However, the examples don’t provide confidence since standard definitions of chronic pain abound, and none would consider pain lasting 30 days as “chronic.” I think that inclusion of studies that explicitly including persons with pain for only the past month is a mistake. Surely, most people experiencing a significant TBI will experience acute head pain, and since TBI in this population commonly is associated with polytrauma, that is, injury to other sites, as well, acute pain may occur in sites other than the head and face, as well.; Multiple other caveats should be noted, even in the Executive Summary. For example, arthritis can be painful, but for many who have a diagnoses of osteoarthritis, for example, pain may be rare (people with the disease can go long periods without any pain, and even then, most “flares” are short in duration) and it can certainly not be assumed that people with a diagnosis of arthritis experience chronic pain.; Also, the currently accepted nomenclature increasing distinguishes “chronic pain” and “high impact chronic pain.” A note about this potentially important distinction would be helpful. | We agree that there are limitations related to broadly defining chronic pain in this manner. Though we include more studies, it is not as clear that all participants met a more conservative definition of chronic pain when the definitions are allowed to vary so greatly. We have attempted to mitigate this concern by providing definitions of chronic pain used in each of the primary studies in the evidence tables. We can also assume that in many cases, when a participant responds that they have had pain for at least 30 days, that the pain lasted longer than that period of time in many cases (i.e., many positive endorsements of this item likely indicate chronic pain, though some cases might possibly reference acute pain lasting just over 30 days). This is particularly likely because many pain assessments were reflective of routine follow-up assessment of pain, not assessments completed at the time of injury (i.e., one can assume that the pain lasted longer than 30 days). Other assumptions such as that a diagnosis of osteoarthritis is associated with chronic pain are well supported in the literature, though our description of the chronic pain measures and definitions in each included study enables readers to select and examine only those with a more narrow and specific definition if they so choose.; Finally, we mention the distinction between chronic pain and high impact chronic pain in the revised discussion section, though note that most included studies were published prior to this terminology being commonly used.
8 | Realizing that many studies reported on prevalence of headache or migraine as a single group, I’m not sure of the value of this approach given that migraine is understood to be a specific condition that is quite distinct from other headache conditions. In the context of mTBI, this difference may be particularly important. | We agree that these are distinct conditions and have now made edits throughout the report to help distinguish these two types of pain conditions. We have reported data for headache and migraine prevalence separately when the distinct data were reported separately in the primary studies. Of the 23 included studies for Key Question 1, only 1 combined headaches and migraines; 4 reported both outcomes separately, and the remaining 18 reported only headaches with no mention of migraines.
8 | Also, as important is the definition used to define mTBI, so I think this should be added. This is not a minor point, since it could have been expected that an answer to key questions hinges on the operational definition of both mTBI and chronic pain that is applied in the search. | We agree and have added a standard definition of mTBI to the report. We chose to include studies with a range of approaches for operationalizing “mTBI” in order to include all available and relevant data for the Key Questions of interest. Though this means that some studies were included that may have used a broader definition of mTBI than that we cited, we have described these approaches in the evidence tables and considered the definitions and operationalizations in the data synthesis. Readers who are interested in a more specific definition or operationalization of “mTBI” can utilize the evidence tables to examine only the studies using definitions relevant to their questions of interest.
8 | Bottom of page 1 (page 9/94) - Reference to “pain medication” includes “non-analgesics” as example; it is unclear what is meant by a non-analgesic pain medication. The authors probably intended to refer to “non-opioids” such as NSAIDS and/or “co-analgesics” such or anti-depressants or gabapentinoids.” This is not a minor point, since many medications have analgesic properties and are commonly used for purposes other than pain management (even NSAIDs). | We appreciate this point. The original publication provides no additional detail about this category of data and the two publications that reported data from the same parent study did not include a category with this label. We have therefore removed “non-analgesic pain medication” from the findings section of the report.
8 | Be more careful in use of terms such as “directly related to mTBI.” (Page 2) How is this term defined? For example, does it mean that the onset was at the same time? Or that there was evidence of trauma to the specific site? Although one might conclude that “headache” could be associated with TBI, that’s not necessarily the case, since headache is known to be common in younger persons including an unknown proportion of SMs prior to their military service. And, of course, TBI is often associated with traumatic injury to other body sites, including painful traumatic injuries. Or pain may emerge in the context of prolonged bed rest and/or activity restrictions and other factors, even other treatments, in the context of acute treatment for TBI. | Thank you for bringing this to our attention. We have revised the language in the report to better represent the variety of circumstances in which individuals with mTBI may experience chronic pain (and, in most cases, our inability to distinguish between them).
8 | I’m not sure how valuable Figure ii is. It seems likely that there are many factors that affect prevalence estimates of chronic pain across studies reporting on specific sites, so it doesn’t seem helpful to know how estimates vary within pain site and to try to compare them across sites, as implied by presenting the estimates in a single figure. | We have included Figure ii to summarize findings from Key Question 1 and not necessarily to compare prevalence levels across pain conditions. We have retained this Figure because we believe it helps depict the state of the science on pain condition prevalence in Veterans and Servicemembers with mTBI.
8 | The first sentence on page 3 should be referenced and information about the methodology, and a critique of the weaknesses of the study, should be provided. The CTBIE should be described. Is it a clinical exam or self-report measure? | Thank you. We have added a citation to this sentence and provided more context about the study, including the CTBIE.
8 | I note that later in the Summary, a point is made that this measure is completed by treatment-seeking patients. Of course, this fact suggests that the estimates of prevalence of chronic pain in such samples will be highly inflated (if one is interested in true population level estimates). The following sentence about an observational study using VA health record data seems at least as relevant; I’m not sure why the estimates reported in this study are questioned whereas the estimates from the former “best” study are not. | We concur that estimates will be greatly influenced based on whether participants are seeking treatment or part of a general, non-treatment seeking sample. We have edited this section to provide better consistency in our evaluation of study samples. Additionally, we have included this consideration in our risk of bias assessment of the included studies and provided detailed information regarding the samples and inclusion criteria to transparently provide readers with information pertaining to potential sources of bias.
8 | On page 3, the term “pain interference” is introduced and should be defined. How was ‘moderate to severe pain” defined? Note that the concept of having pain on half the days in a specific time frame is an accepted way to operationalize “chronic pain” although a minimum three-month period (or six-month) is usually required. | Thank you. We have now defined “pain interference” as well as pain severity levels.
8 | Again, headache and migraine should not be considered as a single “pain type.” They are quite distinct and should not be considered together. Also, note that these diagnoses are known to be poorly identified by clinicians and particularly poorly captured in the electronic record. | As noted above, we have now been more careful to distinguish between these two distinct conditions in the report. We reported prevalence data for the conditions separately when the data were reported separately in the primary studies. Of the 23 included studies for Key Question 1, only one combined headaches and migraines; 4 reported both outcomes separately, and the remaining 18 reported only headaches with no mention of migraines.
8 | The paragraph beginning with “Five studies” on page 3 is not useful without explication of how medication use was employed to define presence of chronic pain. | Thank you. We have clarified this paragraph and revised other locations in the report where pain medication use is used as a proxy measure for chronic pain.
8 | With regard to KQ1b, etiology is apparently solely defined in terms of history of blast-injury and LOC. Another important factor studied in the literature is whether pain is at the site of traumatic injury, so since TBI often occurs in the context of multiple sites of injury, and since sites of pain other than the face or head are being examined, then whether the onset of pain co-occurred with the mTBI may also be important. | This is an interesting point and one that we would like to include in the report. However, the included studies do not report details on polytraumatic sites of injury or timing of pain onset. We have included this point as a potential limitation of the review findings and a gap in the current literature.
8 | With regard to KQ1c, the issue of pain measurement is critical. As already noted, inferring the presence of chronic pain from ICD or medication use data is fraught with problems. In addition, the population from which study samples were derived is also a critical variable. Prevalence estimates from samples of treatment seeking persons will clearly result in inflated estimates. And although some ICD codes specifically include the word “chronic” in the name of the diagnosis, most potentially painful conditions do not. The report from Goulet et al., 2016 noted that a large proportion of Veterans with musculoskeletal diagnoses such as osteoarthritis reported no pain on the date of the diagnosis. Even more problematic is inferring the presence of chronic pain from health record data on medication fills. Greater clarity in the description of the approaches employed both in the studies and during the review is important to encourage confidence in the results of the review. | We agree with the reviewer on each of these assessments. Per our prior responses, we have added text to the report to clarify the pain assessment methods used in each of the studies and to acknowledge the limitations inherent to these methods. We have also now cited the Goulet et al. 2016 paper in the Discussion section of the report.
8 | The bottom line is that the detailed reporting of the prevalence rates reported in the literature is not particularly relevant given all the apparent differences in the methods across studies from which these estimates were derived. It seems to me that it would be more important to summarize the variations and limitations of the literature rather than presenting estimates that are almost certainly unreliable and not meaningful. The conclusion in the paragraph on the top of page 4 should be moved to the front of the summary. | We understand this recommendation. In the revised report, we have taken care to specify the variations and limitations of the literature and to not make inferences based on disparate study types. Additionally, the referenced conclusion statement has now been moved to an earlier section of the Executive Summary to help highlight this point.
8 | Although I was a member of the Technical Expert Panel that helped develop the key questions and approach, in retrospect, it seems that the review was likely misguided. Rates of chronic pain are known to be high among Veterans and SMs. A CDC MMWR published in 2017 reported that Veteran status was specifically and uniquely associated with the presence of chronic pain. Other data on Veterans and SMs also encourage similar conclusions. The key question is not whether prevalence rates are high among Veterans and SMs with histories of mTBI, it’s whether the rates of chronic pain are higher in this subpopulation than among the general population of Veterans and SMs. | We agree with this sentiment. Although the Key Questions and approach remain the same, we have taken this opportunity to revise the results section for Key Question 1 so that, where available, prevalence estimates of chronic pain are included for those with, versus without, a history of mTBI. We have also added a summary of these findings to the Executive Summary and to the Discussion section.
8 | Similarly, KQ3 might have been more appropriately specified as whether there is evidence that Veterans and SMs with mTBI are less likely to accrue benefit from commonly delivered interventions for chronic pain. In the absence of answers to these questions, it seems that current policies for universal screening for the presence and intensity of pain, and for suicide risk assessment, should continue, and that Veterans and SMs with histories of mTBI should continue to be offered evidence-based treatments for chronic pain. | Thank you for this feedback. We have added additional information about this important consideration to the discussion of Key Question 3.
9 | Line 17 P1: Helpful to include databases searched in the summary as described on P10 Search Strategy. | Thank you. This has been added to the summary.
9 | Huge variability in the incidence of headaches - 3 - 98%. What could this be attributed to? | We agree. The wide range is likely due to variation in study design, particularly in samples, pain definitions, and pain ascertainment periods. This has been added to the report.
9 | It is extremely interesting that the analysis started with >2000 pubs but only 31 made the “cut”. Are your inclusion/exclusion criteria too stringent? Can you use some of the studies or parts of studies not meeting criteria? There is a paucity of studies in the area and most of these studies are of poor quality. | Our search terms were purposely broad to identify all possible papers with data on mTBI and pain. This resulted in a large number that were excluded upon review of abstracts or full text. Inclusion and exclusion determinations were based on dual review and consensus. We now include an appendix (Appendix D) table of studies that were excluded after the full text review.
10 | Page 25 line 22–23 has an incomplete sentence. | Thank you. We have edited this sentence.
10 | Table 2: Reference 4 also provided prevalence of “other pain”. This is other musculoskeletal pain including arthritis. If the mixed definition is the reason for exclusion of this, that makes sense. If the authors think this should be included it could be added to the other pain aspect of Table 5 | We agree and have added the data from this reference to the “other pain” section.
10 | For the study examining suicide, it may be worthwhile to also note that the phenotype that transitioned from relatively healthy to Polytrauma phenotype where chronic pain emerged between year 1 and 5 also had significantly higher odds of suicidal ideation/attempt after the phenotype development period. | Thank you. We have added the Moderately Healthy + Decline phenotype to these findings.