# APPENDIX D STUDIES EXCLUDED AT FULL TEXT LEVEL

## Excluded publication type

Barrett RS. Post-traumatic headache. Combat soldiers are suffering. Adv NPs PAs. 2012;3(1):33–34.22355888
Bell KR, Brockway JA, Fann JR, . Concussion treatment after combat trauma: development of a telephone based, problem solving intervention for service members. Contemp Clin Trials. 2015;40:54–62.25460344
Daggett V. Feasibility and satisfaction with the VETeranS Compensate, Adapt, REintegrate (VETS-CARE) intervention. Brain Inj. 2014;28(5–6):554.
DePalma RG. Combat TBI: History, Epidemiology, and Injury Modes. CRC Press/Taylor & Francis. 2015;2.
Eskridge SL. Combat-related blast injuries: Injury types and outcomes. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2012;72(7-B):3929.
Finkel A. Headaches in soldiers with mild traumatic brain injury-additional data. Headache. 2012;52(8):1320.22747500
Gelinas C. Validation of a revised pain assessment tool for brain-injured ICU patients. Critical care medicine Conference: 46th critical care congress of the society of critical care medicine, SCCM. 2016;44(12 Supplement 1):269.
Hoffer ME, Donaldson C, Gottshall KR, Balaban C, Balough BJ. Blunt and blast head trauma: different entities. Int Tinnitus J. 2009;15(2):115–118.20420334
Hoffman JM, Ehde DM, Dikmen S, . Telephone-delivered cognitive behavioral therapy for veterans with chronic pain following traumatic brain injury: Rationale and study protocol for a randomized controlled trial study. Contemp Clin Trials. 2019;76:112–119.30553077
Khoury S, Benavides R. Pain with traumatic brain injury and psychological disorders. Prog Neuropsychopharmacol Biol Psychiatry. 2018;87(Pt B):224–233.28627447
Kjeldgaard D, Forchhammer H, Jensen R. Cognitive, emotional and somatic symptoms among patients with chronic posttraumatic headache. A controlled study…The European Headache and Migraine Trust International Congress, London, UK. 20–23 September 2012. J Headache Pain. 2013;14:1–1.23566305
Kumar A, Loane DJ. Neuroinflammation after traumatic brain injury: opportunities for therapeutic intervention. Brain, behavior, and immunity. 2012;26(8):1191–1201.
Malozzi SL. Predicting clinical outcomes in OEF/OIF/OND veterans with the polytrauma clinical triad. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2019;80(2-B(E)):No-Specified.
Mehalick ML, Glueck AC. Examining the relationship and clinical management between traumatic brain injury and pain in military and civilian populations. Brain Inj. 2018;32(11):1307–1314.29993307
Metti A. Post-traumatic vs non-traumatic headaches: a phenotypic analysis. Neurology. 2018;90(15).
Nassif TH. Examining the effectiveness of mindfulness meditation for chronic pain management in combat Veterans with traumatic brain injury. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2014;75(3-B(E)):No-Specified.
NCT00862095. Medical Therapies for Chronic Post-Traumatic Headaches. A Randomized Controlled Trial of Medical Therapies for Chronic Post-Traumatic Headaches. 2009.
NCT01306968. Hyperbaric Oxygen Therapy (HBO2) for Persistent Post-concussive Symptoms After Mild Traumatic Brain Injury (mTBI). In. Research USAM, Materiel Command Y, trans2011.
NCT01611194. mTBI Mechanisms of Action of HBO2 for Persistent Post-Concussive Symptoms. In. Research USAM, Materiel Command Y, trans2012.
O’Connor KL. Concussion among military service academy members: Identifying risk factors, recovery trajectories, and the role of mental health. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2018;79(12-B(E)):No-Specified.
Ruff RL, Riechers RG, Ruff SS. Relationships between mild traumatic brain injury sustained in combat and post-traumatic stress disorder. F1000 Med Rep. 2010;2:64.21173852
Saper RB, Lemaster CM, Elwy AR, . Yoga versus education for Veterans with chronic low back pain: study protocol for a randomized controlled trial. Trials. 2016;17(1):224.27129472
Tang V, Warden J, Cullen N, Rutledge E. Topiramate in traumatic brain injury: Adverse effects on cognitive function. The Journal of Head Trauma Rehabilitation. 2007;22(6):409–410.18025973
Tepper D. Post-traumatic headache in veterans. Headache. 2013;53(5):875–876.23614524
Theeler B, Lucas S, Riechers RG, 2nd, Ruff RL. Post-traumatic headaches in civilians and military personnel: a comparative, clinical review. Headache. 2013;53(6):881–900.23721236
Wortman K. Personality and executive functioning in male veterans with mild traumatic brain injury. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2018;79(1-B(E)):No-Specified.
Zhang K, Jiang W, Ma T, Wu H. Comparison of early and late decompressive craniectomy on the long-term outcome in patients with moderate and severe traumatic brain injury: A metaanalysis. Br J Neurosurg. 2016;30(2):251–257.26828333

## Excluded population

Adams RS, Larson MJ, Meerwijk EL, Williams TV, Harris AHS. Postdeployment Polytrauma Diagnoses Among Soldiers and Veterans Using the Veterans Health Affairs Polytrauma System of Care and Receipt of Opioids, Nonpharmacologic, and Mental Health Treatments. J Head Trauma Rehabil. 2019;34(3):167–175.31058759
Afari N, Pittman J, Floto E, . Differential impact of combat on postdeployment symptoms in female and male veterans of Iraq and Afghanistan. Mil Med. 2015;180(3):296–303.25735020
Arbisi PA, Polusny MA, Erbes CR, Thuras P, Reddy MK. The Minnesota Multiphasic Personality Inventory-2 Restructured Form in National Guard soldiers screening positive for posttraumatic stress disorder and mild traumatic brain injury. Psychol Assess. 2011;23(1):203–214.21381845
Avallone KM, Smith ER, Ma S, . PTSD as a Mediator in the Relationship Between PostConcussive Symptoms and Pain Among OEF/OIF/OND Veterans. Mil Med. 2019;184(12):e118–e123.30215758
Balba NM, Elliott JE, Weymann KB, . Increased Sleep Disturbances and Pain in Veterans with Comorbid Traumatic Brain Injury and Posttraumatic Stress Disorder. J Clin Sleep Med. 2018;14(11):1865–1878.30373686
Bertenthal D, Yaffe K, Barnes DE, . Do postconcussive symptoms from traumatic brain injury in combat veterans predict risk for receiving opioid therapy for chronic pain? Brain Inj. 2018;32(10):1188–1196.29985653
Blakey SM, Wagner HR, Naylor J, . Chronic Pain, TBI, and PTSD in Military Veterans: A Link to Suicidal Ideation and Violent Impulses? J Pain. 2018;19(7):797–806.29526669
Bomyea J, Lang AJ, Delano-Wood L, . Neuropsychiatric Predictors of Post-Injury Headache After Mild-Moderate Traumatic Brain Injury in Veterans. Headache. 2016;56(4):699–710.27028095
Bryan CJ, Hernandez AM. Predictors of post-traumatic headache severity among deployed military personnel. Headache. 2011;51(6):945–953.21457255
Bushnik T, Englander J, Wright J. The experience of fatigue in the first 2 years after moderateto-severe traumatic brain injury: a preliminary report. J Head Trauma Rehabil. 2008;23(1):17–24.18219231
Carlozzi NE, Kisala PA, Boulton AJ, . Measuring Pain in TBI: Development of the TBI-QOL Pain Interference Item Bank and Short Form. Arch Phys Med Rehabil. 2020;101(1):11–19.31562878
Carlson KF, Taylor BC, Hagel EM, Cutting A, Kerns R, Sayer NA. Headache diagnoses among Iraq and Afghanistan war veterans enrolled in VA: a gender comparison. Headache. 2013;53(10):1573–1582.24102376
Cifu DX, Taylor BC, Carne WF, . Traumatic brain injury, posttraumatic stress disorder, and pain diagnoses in OIF/OEF/OND Veterans. J Rehabil Res Dev. 2013;50(9):1169–1176.24458958
Cohen SP, Plunkett AR, Wilkinson I, . Headaches during war: analysis of presentation, treatment, and factors associated with outcome. Cephalalgia. 2012;32(2):94–108.21994113
Combs MA, Critchfield EA, Soble JR. Relax while you rehabilitate: A pilot study integrating a novel, yoga-based mindfulness group intervention into a residential military brain injury rehabilitation program. Rehabil Psychol. 2018;63(2):182–193.29528664
Copeland LA, Finley EP, Bollinger MJ, Amuan ME, Pugh MJ. Comorbidity Correlates of Death Among New Veterans of Iraq and Afghanistan Deployment. Med Care. 2016;54(12):1078–1081.27367868
Davis L, Hanson B, Gilliam S. Pilot study of the effects of mixed light touch manual therapies on active duty soldiers with chronic post-traumatic stress disorder and injury to the head. J Bodywork Mov Ther. 2016;20(1):42–51.
Denby E, Murphy D, Busuttil W, Sakel M, Wilkinson D. Neuropsychiatric Outcomes in UK Military Veterans with Mild Traumatic Brain Injury and Vestibular Dysfunction. J Head Trauma Rehabil. 2020;35(1):57–65.30829817
Detweiler MB, Arif S, Candelario J, . Salem VAMC-U.S. Army Fort Bragg Warrior Transition Clinic telepsychiatry collaboration: 12-month operation clinical perspective. Telemed J E Health. 2012;18(2):81–86.22283361
Eagle SR, Kontos AP, Mi QI, . Shared Neuromuscular Performance Traits in Military Personnel with Prior Concussion. Med Sci Sports Exerc. 2019;51(8):1619–1625.30845049
Elbogen EB, Alsobrooks A, Battles S, . Mobile Neurofeedback for Pain Management in Veterans with TBI and PTSD. Pain Med. 2019;07:07.
Elnitsky CA, Blevins C, Findlow JW, Alverio T, Wiese D. Student Veterans Reintegrating from the Military to the University With Traumatic Injuries: How Does Service Use Relate to Health Status? Arch Phys Med Rehabil. 2018;99(2S):S58–S64.29097180
Epstein EL, Martindale SL, Va Mid-Atlantic Mirecc W, Miskey HM. Posttraumatic stress disorder and traumatic brain Injury: Sex differences in veterans. Psychiatry Research. 2019;274:105–111.30784779
Eskridge SL, Macera CA, Galarneau MR, . Influence of combat blast-related mild traumatic brain injury acute symptoms on mental health and service discharge outcomes. J Neurotrauma. 2013;30(16):1391–1397.23489170
Finkel AG, Yerry JA, Klaric JS, Ivins BJ, Scher A, Choi YS. Headache in military service members with a history of mild traumatic brain injury: A cohort study of diagnosis and classification. Cephalalgia. 2017;37(6):548–559.27206963
Finley EP, Bollinger M, Noel PH, . A national cohort study of the association between the polytrauma clinical triad and suicide-related behavior among US Veterans who served in Iraq and Afghanistan. Am J Public Health. 2015;105(2):380–387.25033126
Fonda JR, Gradus JL, Brogly SB, McGlinchey RE, Milberg WP, Fredman L. Traumatic Brain Injury and Opioid Overdose Among Post-9/11 Veterans with Long-Term Opioid Treatment of Chronic Pain. J Head Trauma Rehabil. 2019;08:08.
Golub A, Bennett AS. Prescription opioid initiation, correlates, and consequences among a sample of OEF/OIF military personnel. Subst Use Misuse. 2013;48(10):811–820.23869455
Harch PG, Andrews SR, Fogarty EF, Lucarini J, Van Meter KW. Case control study: hyperbaric oxygen treatment of mild traumatic brain injury persistent post-concussion syndrome and post-traumatic stress disorder. Medical Gas Research. 2017;7(3):156–174.29152209
Hershaw JN, Hill-Pearson CA, Arango JI, Souvignier CAR, Pazdan CRM. Semi-Automated Neurofeedback Therapy for Persistent Postconcussive Symptoms in a Military Clinical Setting: A Feasibility Study. Mil Med. 2019;11:11.
Higgins DM, Kerns RD, Brandt CA, . Persistent pain and comorbidity among Operation Enduring Freedom/Operation Iraqi Freedom/operation New Dawn veterans. Pain Med. 2014;15(5):782–790.24548466
Higgins DM. Internet-based Pain Self-management for Veterans: Feasibility and Preliminary Efficacy of the Pain EASE Program. Pain Practice. 2020;20(4):357–370.31778281
Hoffman SN, Herbert MS, Crocker LD, . The Role of Pain Catastrophizing in Cognitive Functioning Among Veterans with a History of Mild Traumatic Brain Injury. J Head Trauma Rehabil. 2019;34(4):E61–E66.
Howard L, Dumkrieger G, Chong CD, Ross K, Berisha V, Schwedt TJ. Symptoms of Autonomic Dysfunction Among Those with Persistent Posttraumatic Headache Attributed to Mild Traumatic Brain Injury: A Comparison to Migraine and Healthy Controls. Headache. 2018;58(9):1397–1407.30156267
Hudson TJ, Painter JT, Gressler LE, . Factors Associated with Opioid Initiation in OEF/OIF/OND Veterans with Traumatic Brain Injury. Pain Med. 2018;19(4):774–787.29036680
Hudson TJ, Painter JT, Martin BC, . Pharmacoepidemiologic analyses of opioid use among OEF/OIF/OND veterans. Pain. 2017;158(6):1039–1045.28195856
Jaramillo CA, Cooper DB, Wang CP, . Subgroups of US IRAQ and Afghanistan veterans: associations with traumatic brain injury and mental health conditions. Brain Imaging Behav. 2015;9(3):445–455.25963862
Jaramillo CA, Eapen BC, McGeary CA, . A cohort study examining headaches among veterans of Iraq and Afghanistan wars: Associations with traumatic brain injury, PTSD, and depression. Headache. 2016;56(3):528–539.26688427
Johansson B, Wentzel AP, Andréll P, Mannheimer C, Rönnbäck L. Methylphenidate reduces mental fatigue and improves processing speed in persons suffered a traumatic brain injury. Brain Inj. 2015;29(6):758–765.25794299
Johnson SS, Levesque DA, Broderick LE, Bailey DG, Kerns RD. Pain Self-Management for Veterans: Development and Pilot Test of a Stage-Based Mobile-Optimized Intervention. JMIR Med Inform. 2017;5(4):e40.29042341
Jonas WB, Bellanti DM, Paat CF, . A Randomized Exploratory Study to Evaluate Two Acupuncture Methods for the Treatment of Headaches Associated with Traumatic Brain Injury. Med Acupunct. 2016;28(3):113–130.27458496
Jouzdani SR, Ebrahimi A, Rezaee M, Shishegar M, Tavallaii A, Kaka G. Characteristics of posttraumatic headache following mild traumatic brain injury in military personnel in Iran. Environ. 2014;19(6):422–428.
King PR, Beehler GP, Wade MJ. Self-Reported Pain and Pain Management Strategies Among Veterans with Traumatic Brain Injury: A Pilot Study. Mil Med. 2015;180(8):863–868.26226528
Kjeldgaard Nielsen D FHTTWJRH. EHMTI-0162. Cognitive behavioural treatment for the chronic posttraumatic headache patient: a randomised controlled trial. Journal of headache and pain. 2014;15.
Lang KP, Veazey-Morris K, Andrasik F. Exploring the role of insomnia in the relation between PTSD and pain in veterans with polytrauma injuries. J Head Trauma Rehabil. 2014;29(1):44–53.23835878
Lee CJ, Felix ER, Levitt RC, . Traumatic brain injury, dry eye and comorbid pain diagnoses in US veterans. Br J Ophthalmol. 2018;102(5):667–673.28844048
Losoi H, Silverberg ND, Waljas M, . Resilience Is Associated with Outcome from Mild Traumatic Brain Injury. J Neurotrauma. 2015;32(13):942–949.25764398
Mahmood S, Al-Thani H, El-Menyar A, . Tramadol in traumatic brain injury: Should we continue to use it? Journal of Anaesthesiology Clinical Pharmacology. 2015;31(3):344–348.
Martindale SL, Epstein EL, Taber KH, Workgroup VAM-AM, Rowland JA. Behavioral and Health Outcomes Associated with Deployment and Nondeployment Acquisition of Traumatic Brain Injury in Iraq and Afghanistan Veterans. Arch Phys Med Rehabil. 2018;99(12):2485–2495.29859179
Miller RS, Weaver LK, Bahraini N, . Effects of hyperbaric oxygen on symptoms and quality of life among service members with persistent postconcussion symptoms: a randomized clinical trial. JAMA Intern Med. 2015;175(1):43–52.25401463
Moeller DR, Duffey JM, Goolsby AM, Gallimore JT. Use of a Removable Mandibular Neuroprosthesis for the Reduction of Posttraumatic Stress Disorder (PTSD) and Mild Traumatic Brain Injury/PTSD/Associated Nightmares, Headaches, and Sleep Disturbances. J Spec Oper Med. 2014;14(3):64–73.25344709
Moriarty H, Winter L, Robinson K, . Exploration of Individual and Family Factors Related to Community Reintegration in Veterans with Traumatic Brain Injury. Journal of the American Psychiatric Nurses Association. 2015;21(3):195–211.26156059
Mortera MH, Kinirons SA, Simantov J, Klingbeil H. Long-Term Neurobehavioral Symptoms and Return to Productivity in Operation Enduring Freedom/Operation Iraqi Freedom Veterans with and Without Traumatic Brain Injury. Arch Phys Med Rehabil. 2018;99(2S):S50–S57.28088381
Norris JN, Smith S, Harris E, Labrie DW, Ahlers ST. Characterization of acute stress reaction following an IED blast-related mild traumatic brain injury. Brain Inj. 2015;29(7–8):898–904.25955118
Paltsev AI, Torgashov MN, Voronova YS, Bayandina EV, Lunyakina SB. Role of combat stress in the formation of chronic pain syndrome in combatants and its treatment with pantogam active. Neuroscience and Behavioral Physiology. 2011;41(8):878–882.
Phillips KM, Clark ME, Gironda RJ, . Pain and psychiatric comorbidities among two groups of Iraq and Afghanistan era Veterans. J Rehabil Res Dev. 2016;53(4):413–432.27532156
Pugh MJ, Finley EP, Wang CP, . A retrospective cohort study of comorbidity trajectories associated with traumatic brain injury in veterans of the Iraq and Afghanistan wars. Brain Inj. 2016;30(12):1481–1490.27834535
Ribeiro CJN, Araujo ACS, Brito SB, . Pain assessment of traumatic brain injury victims using the Brazilian version of the Behavioral Pain Scale. Revista Brasileira de Terapia Intensiva. 2018;30(1):42–49.29742216
Rosenthal JF, Erickson JC. Post-traumatic stress disorder in U.S. soldiers with post-traumatic headache. Headache. 2013;53(10):1564–1572.24001181
Sayer NA, Cifu DX, McNamee S, . Rehabilitation needs of combat-injured service members admitted to the VA Polytrauma Rehabilitation Centers: the role of PM&R in the care of wounded warriors. Pm R. 2009;1(1):23–28.19627869
Scott BR, Uomoto JM, Barry ES. Impact of Pre-Existing Migraine and Other Co-Morbid or Co-Occurring Conditions on Presentation and Clinical Course Following Deployment-Related Concussion. Headache. 2020;03:03.
Seal KH, Bertenthal D, Barnes DE, . Traumatic Brain Injury and Receipt of Prescription Opioid Therapy for Chronic Pain in Iraq and Afghanistan Veterans: Do Clinical Practice Guidelines Matter? J Pain. 2018;19(8):931–941.29597083
Shah A, Ayala M, Capra G, Fox D, Hoffer M. Otologic assessment of blast and nonblast injury in returning Middle East-deployed service members. Laryngoscope. 2014;124(1):272–277.23686673
Shan K, Cao W, Yuan Y, . Use of the critical-care pain observation tool and the bispectral index for the detection of pain in brain-injured patients undergoing mechanical ventilation: A STROBE-compliant observational study. Medicine (Baltimore). 2018;97(22):e10985–e10985.29851854
Sheng T, Fairchild JK, Kong JY, . The influence of physical and mental health symptoms on Veterans’ functional health status. J Rehabil Res Dev. 2016;53(6):781–796.28273324
Stilling Jm PEMLJGLSWMAFDSPMODCT. Treatment of persistent post-traumatic headache and post-concussion symptoms using rTMS: a pilot, double-blind, randomized controlled trial. J Neurotrauma. 2019.
Strigo IA, Spadoni AD, Inslicht SS, Simmons AN. Repeated Exposure to Experimental Pain Differentiates Combat Traumatic Brain Injury with and without Post-Traumatic Stress Disorder. J Neurotrauma. 2018;35(2):297–307.28931334
Strigo IA, Spadoni AD, Lohr J, Simmons AN. Too hard to control: compromised pain anticipation and modulation in mild traumatic brain injury. Transl Psychiatry. 2014;4:e340.24399043
Tan G, Fink B, Dao TK, . Associations among pain, PTSD, mTBI, and heart rate variability in veterans of Operation Enduring and Iraqi Freedom: a pilot study. Pain Med. 2009;10(7):1237–1245.19818034
Taylor BC, Hagel EM, Carlson KF, . Prevalence and costs of co-occurring traumatic brain injury with and without psychiatric disturbance and pain among Afghanistan and Iraq War Veteran V.A. users. Med Care. 2012;50(4):342–346.22228249
Terrio H, Brenner LA, Ivins BJ, . Traumatic brain injury screening: preliminary findings in a US Army Brigade Combat Team. J Head Trauma Rehabil. 2009;24(1):14–23.19158592
Theeler BJ, Erickson JC. Mild head trauma and chronic headaches in returning US soldiers. Headache. 2009;49(4):529–534.19220499
Tschiffely AE, Haque A, Haran FJ, . Recovery from Mild Traumatic Brain Injury Following Uncomplicated Mounted and Dismounted Blast: A Natural History Approach. Mil Med. 2018;183(3–4):e140–e147.
Van Pelt KL, Allred D, Cameron KL, . A cohort study to identify and evaluate concussion risk factors across multiple injury settings: findings from the CARE Consortium. Inj Epidemiol. 2019;6(1):1.30637568
Vanderploeg RD, Belanger HG, Horner RD, . Health outcomes associated with military deployment: mild traumatic brain injury, blast, trauma, and combat associations in the Florida National Guard. Arch Phys Med Rehabil. 2012;93(11):1887–1895.22705240
Walker WC, Seel RT, Curtiss G, Warden DL. Headache after moderate and severe traumatic brain injury: a longitudinal analysis. Arch Phys Med Rehabil. 2005;86(9):1793–1800.16181945
Weaver LK, Wilson SH, Lindblad AS, . Hyperbaric oxygen for post-concussive symptoms in United States military service members: a randomized clinical trial. Undersea Hyperb Med. 2018;45(2):129–156.29734566
Williams KA, Lawson RM, Perurena OH, Coppin JD. Management of Chronic Migraine and Occipital Neuralgia in Post 9/11 Combat Veterans. Mil Med. 2019;184(7–8):e207–e211.30690565
Winter L, Moriarty H, Robinson K. Employment Status Among U.S. Military Veterans with Traumatic Brain Injury: Mediation Analyses and the Goal of Tertiary Prevention. Front Neurol. 2019;10:190.30930830
Winter L, Moriarty HJ, Robinson K, . Efficacy and acceptability of a home-based, family-inclusive intervention for veterans with TBI: A randomized controlled trial. Brain Inj. 2016;30(4):373–387.26983578
Wojtowicz M, Silverberg ND, Bui E, Zafonte R, Simon N, Iverson GL. Psychiatric Comorbidity and Psychosocial Problems Among Treatment-Seeking Veterans with a History of Mild Traumtic Brain Injury. Focus (Am Psychiatr Publ). 2017;15(4)384–389.
Wolf G, Cifu D, Baugh L, Carne W, Profenna L. The effect of hyperbaric oxygen on symptoms after mild traumatic brain injury. J Neurotrauma. 2012;29(17):2606–2612.23031217

## No outcome of interest

Aase DM, Babione JM, Proescher E, . Impact of PTSD on post-concussive symptoms, neuropsychological functioning, and pain in post-9/11 veterans with mild traumatic brain injury. Psychiatry Research. 2018;268:460–466.30138858
Armed Forces Health Surveillance C. Incident diagnoses of common symptoms ("sequelae") following traumatic brain injury, active component, U.S. Armed Forces, 2000–2012. MSMR. 2013;20(6):9–13.
Betthauser LM, Brenner LA, Cole W, Scher AI, Schwab K, Ivins BJ. A Clinical Evidence-Based Approach to Examine the Effects of mTBI and PTSD Symptoms on ANAM Performance in Recently Deployed Active Duty Soldiers: Results from the Warrior Strong Study. J Head Trauma Rehabil. 2018;33(2):91–100.29517590
Cook AJ, Meyer EC, Evans LD, . Chronic pain acceptance incrementally predicts disability in polytrauma-exposed veterans at baseline and 1-year follow-up. Behav Res Ther. 2015;73:25–32.26233854
Cooper DB, Chau PM, Armistead-Jehle P, . Relationship between mechanism of injury and neurocognitive functioning in OEF/OIF service members with mild traumatic brain injuries. Mil Med. 2012;177(10):1157–1160.23113441
Finkel AG, Ivins BJ, Yerry JA, Klaric JS, Scher A, Sammy Choi Y. Which Matters More? A Retrospective Cohort Study of Headache Characteristics and Diagnosis Type in Soldiers with mTBI/Concussion. Headache. 2017;57(5):719–728.28239838
Finkel AG, Klaric JS, Yerry JA, Choi YS. Staying in service with posttraumatic headache: A retrospective cohort study of patient outcome. Neurology. 2017;89(11):1186–1194.28814458
Finkel AG, Yerry J, Scher A, Choi YS. Headaches in soldiers with mild traumatic brain injury: findings and phenomenologic descriptions. Headache. 2012;52(6):957–965.22568576
Kanefsky R, Motamedi V, Mithani S, Mysliwiec V, Gill JM, Pattinson CL. Mild traumatic brain injuries with loss of consciousness are associated with increased inflammation and pain in military personnel. Psychiatry Research. 2019;279:34–39.31280036
Klaric JS, Forbes LL, Finkel AG. Painful Craniofacial/Cervical Surface Area and Continuous Headache After Military Concussion: A Morphometric Retrospective Cohort Study. Headache. 2018;58(9):1457–1464.30362523
Kozminski M. Combat-related posttraumatic headache: diagnosis, mechanisms of injury, and challenges to treatment. J Am Osteopath Assoc. 2010;110(9):514–519.20876836
Lindquist LK, Love HC, Elbogen EB. Traumatic Brain Injury in Iraq and Afghanistan Veterans: New Results from a National Random Sample Study. J Neuropsychiatry Clin Neurosci. 2017;29(3):254–259.28121256
Mac Donald CL, Johnson AM, Wierzechowski L, . Prospectively assessed clinical outcomes in concussive blast vs nonblast traumatic brain injury among evacuated US military personnel. JAMA Neurol. 2014;71(8):994–1002.24934200
Merritt VC, Jurick SM, Crocker LD, . Associations Between Multiple Remote Mild TBIs and Objective Neuropsychological Functioning and Subjective Symptoms in Combat-Exposed Veterans. Arch Clin Neuropsychol. 2020;02:02.
Romesser J, Shen S, Reblin M, . A preliminary study of the effect of a diagnosis of concussion on PTSD symptoms and other psychiatric variables at the time of treatment seeking among veterans. Mil Med. 2011;176(3):246–252.21456348
Seidl JN, Pastorek NJ, Lillie R, . Factors related to satisfaction with life in veterans with mild traumatic brain injury. Rehabil Psychol. 2015;60(4):335–343.26618214
Song K, Wang CP, McGeary DD, . Five-year Pain Intensity and Treatment Trajectories of Post-9/11 Veterans with Mild Traumatic Brain Injury. J Pain. 2020;22:22.
Stewart-Willis JJ, Heyanka D, Proctor-Weber Z, England H, Bruhns M. Premorbid IQ Predicts Postconcussive Symptoms in OEF/OIF/OND Veterans with mTBI. Arch Clin Neuropsychol. 2018;33(2):206–215.28595276
Stojanovic MP, Fonda J, Fortier CB, . Influence of Mild Traumatic Brain Injury (TBI) and Posttraumatic Stress Disorder (PTSD) on Pain Intensity Levels in OEF/OIF/OND Veterans. Pain Med. 2016;17(11):2017–2025.27040665
Stratton KJ, Hawn SE, Amstadter AB, Cifu DX, Walker WC. Correlates of pain symptoms among Iraq and Afghanistan military personnel following combat-related blast exposure. J Rehabil Res Dev. 2014;51(8):1189–1202.25789376
Swan AA, Amuan ME, Morissette SB, . Long-term physical and mental health outcomes associated with traumatic brain injury severity in post-9/11 veterans: A retrospective cohort study. Brain Inj. 2018;32(13–14):1637–1650.30273517
Theeler BJ, Flynn FG, Erickson JC. Headaches after concussion in US soldiers returning from Iraq or Afghanistan. Headache. 2010;50(8):1262–1272.20553333
Walker WC, Franke LM, Sima AP, Cifu DX. Symptom Trajectories After Military Blast Exposure and the Influence of Mild Traumatic Brain Injury. J Head Trauma Rehabil. 2017;32(3):E16–E26.
Walker WC, Nowak KJ, Kenney K, . Is balance performance reduced after mild traumatic brain injury?: Interim analysis from chronic effects of neurotrauma consortium (CENC) multicentre study. Brain Inj. 2018;32(10):1156–1168.29894203
Wu E, Graham DP. Association of Chronic Pain and Community Integration of Returning Veterans with and Without Traumatic Brain Injury. J Head Trauma Rehabil. 2016;31(1):E1–12.

## Excluded study design

Baker VB, Eliasen KM, Hack NK. Lifestyle modifications as therapy for medication refractory post-traumatic headache (PTHA) in the military population of Okinawa. J Headache Pain. 2018;19(1):113.30466384
Erickson JC. Treatment outcomes of chronic post-traumatic headaches after mild head trauma in US soldiers: an observational study. Headache. 2011;51(6):932–944.21592097
Hoot MR, Khokhar B, Walker WC. Self-report Pain Scale Reliability in Veterans and Service Members with Traumatic Brain Injuries Undergoing Inpatient Rehabilitation. Mil Med. 2019;09:09.
Janak JC, Cooper DB, Bowles AO, . Completion of Multidisciplinary Treatment for Persistent Postconcussive Symptoms Is Associated with Reduced Symptom Burden. J Head Trauma Rehabil. 2017;32(1):1–15.26709579
Leung A, Fallah A, Shukla S, . rTMS in Alleviating Mild TBI Related Headaches-A Case Series. Pain physician. 2016;19(2):E347–E354.26815263
Ruff RL, Riechers RG, 2nd, Wang XF, Piero T, Ruff SS. For veterans with mild traumatic brain injury, improved posttraumatic stress disorder severity and sleep correlated with symptomatic improvement. J Rehabil Res Dev. 2012;49(9):1305–1320.23408213
Ruff RL, Ruff SS, Wang XF. Improving sleep: initial headache treatment in OIF/OEF veterans with blast-induced mild traumatic brain injury. J Rehabil Res Dev. 2009;46(9):1071–1084.20437313
Yerry JA, Kuehn D, Finkel AG. Onabotulinum Toxin A for the Treatment of Headache in Service Members with a History of Mild Traumatic Brain Injury: A Cohort Study. Headache: The Journal of Head & Face Pain. 2015;55(3):395–406.

## Duplicate publication of included study

Ferdosi H, Schwab KA, Metti A, . Trajectory of Postconcussive Symptoms 12 Months After Deployment in Soldiers with and Without Mild Traumatic Brain Injury: Warrior Strong Study. Am J Epidemiol. 2019;188(1):77–86.30203085
Lippa SM, Fonda JR, Fortier CB, . Deployment-related psychiatric and behavioral conditions and their association with functional disability in OEF/OIF/OND veterans. J Trauma Stress. 2015;28(1):25–33.25703936