# APPENDIX C QUALITY ASSESSMENT

Table 10 Criteria used in quality assessment of randomized controlled trials

Cochrane RoB 2.0:^33^ Five domains through which bias may be introduced
1. Risk of bias arising from the randomization process:; 1.1 Was the allocation sequence random?; 1.2 Was the allocation sequence concealed until participants were enrolled and assigned to interventions?; 1.3 Did baseline differences between intervention groups suggest a problem with the randomization process?
2. Risk of bias due to deviations from the intended interventions (effect of assignment to intervention):; 2.1 Were participants aware of their assigned intervention during the trial?; 2.2 Were carers and people delivering the interventions aware of participants’ assigned intervention during the trial?; 2.3 If Y/PY/NI to 2.1 or 2.2: Were there deviations from the intended intervention that arose because of the experimental context?; 2.4 If Y/PY to 2.3: Were these deviations from intended intervention balanced between groups?; 2.5 If N/PN/NI to 2.4: Were these deviations likely to have affected the outcome?; 2.6 Was an appropriate analysis used to estimate the effect of assignment to intervention?; 2.7 If N/PN/NI to 2.6: Was there potential for a substantial impact (on the result) of the failure to analyze participants in the group to which they were randomized?
3. Risk of bias due to missing outcome data:; 3.1 Were data for this outcome available for all, or nearly all, participants randomized?; 3.2 If N/PN/NI to 3.1: Is there evidence that the result was not biased by missing outcome data?; 3.3 If N/PN to 3.2: Could missingness in the outcome depend on its true value?; 3.4 If Y/PY/NI to 3.3: Is it likely that missingness in the outcome depended on its true value?
4. Risk of bias in measurement of the outcome:; 4.1 Was the method of measuring the outcome inappropriate?; 4.2 Could measurement or ascertainment of the outcome have differed between intervention groups?; 4.3 If N/PN/NI to 4.1 and 4.2: Were outcome assessors aware of the intervention received by study participants ?; 4.4 If Y/PY/NI to 4.3: Could assessment of the outcome have been influenced by knowledge of intervention received?; 4.5 If Y/PY/NI to 4.4: Is it likely that assessment of the outcome was influenced by knowledge of intervention received?
5. Risk of bias in selection of the reported result:; 5.1 5.1 Were the data that produced this result analyzed in accordance with a pre-specified analysis plan that was finalized before unblinded outcome data were available for analysis?; Is the numerical result being assessed likely to have been selected, on the basis of the results, from…; 5.2 …multiple outcome measurements (eg scales, definitions, time points) within the outcome domain?; 5.3 …multiple analyses of the data?
Overall risk-of-bias judgement
Low ROB | The study is judged to be at low risk of bias for all domains for this result.
Some Concerns | The study is judged to raise some concerns in at least 1 domain for this result, but not to be at high risk of bias for any domain.
High ROB | The study is judged to be at high risk of bias in at least 1 domain for this result.; OR; The study is judged to have some concerns for multiple domains in a way that substantially lowers confidence in the result.

Abbreviations: NI=not indicated; N=no; PN=probably not; PY=probably yes; ROB=risk of bias; Y=yes

Table 11 Quality ratings for studies reporting prevalence of chronic pain in Veterans/Servicemembers with history of mild traumatic brain injury

Study Author, year | #1 | #2 | #3 | #4 | Overall study quality/Quality concerns | Applicability
Beswick-Escanlar, 2016^45^ | 1 | NA | 0 | 0 | Entire population of SMs and focused on incident mTBI with incident headache or migraine pain (no diagnosis codes prior to study start date) during 1-year follow-up period. Both mTBI and pain were defined as ≥1 diagnosis code. | Post-9/11 SMs receiving military health care between 2006 and 2015.
Brickell, 2014^42^ | 1 | 0 | 0 | 0 | Small sample size, and different patients at each follow-up. High attrition; no report of non-responder characteristics. mTBI definition inconsistent with VA-DoD common definition (required LOC<15 minutes and allowed intracranial abnormality). Non-standard pain measure (based on open-ended telephone interview questions). | Post-9/11 SMs with mTBI and polytrauma.
Couch, 2016^46^ | 0 | 0 | 1 | 0 | Small sample size; highly selective patient group treated in 1 reintegration clinic. mTBI assessed clinically according to VA/DoD common definition. Headache or migraine pain self-reported based on clinical assessment questionnaire. | Male, Post-9/11 Veterans at 1 site, between ages of 20 and 60, enrolled in reintegration clinic.
Farrell-Carnahan, 2015^47^ | 1 | 0 | 1 | 1 | Small study of Post-9/11 Veterans admitted to inpatient rehabilitation at 1 of 4 VA polytrauma rehabilitation centers and enrolled in TBI Model Systems. mTBI assessed using TBI Model Systems form. Headache intensity assessed using single item from NSI. Differences between participants (80% of those recruited) and non-participants (20% of recruited) are unclear. | Post-9/11 Veterans requiring inpatient rehabilitation for TBI and who enroll in VA TBI Model Systems.
Hoge, 2008^15^ | 1 | 0 | 0 | 1 | Survey with 59% response rate, no information on non-respondents. mTBI assessed using screening questions; mTBI group included n=4 with LOC>30 mins. Pain measures assessed using validated instrument. | Post-9/11 Army SMs shortly after return from combat deployment.
Hoot, 2018^41^,^†^ | 1 | 0 | 1 | 1 | Fairly selective study sample from 4 sites (no information on Veterans/SMs who were recruited but did not enroll). Standardized and validated measures of mTBI and pain were used. | Post-9/11 Veterans/SMs with combat exposure enrolled in a comprehensive longitudinal study.
Jackson, 2016^48^ | 1 | 0 | 1 | 0 | Veterans sampled nationally. mTBI assessed using VA 4-item screen plus clinical interview. Headache pain assessed using post-concussive symptom indicators on VA 4-item screen. | Post-9/11 Veterans who received mental health evaluation in VA; oversampled females and Veterans with PTSD.
King, 2014^40^ | 1 | NA | 0 | 0 | Entire population of VA users across region. mTBI defined using ≥1 ICD diagnosis code for post-concussion syndrome. Pain conditions also based on ICD diagnosis codes. | Post-9/11 Veterans who used VA primary care in VISN 2.
Kulas, 2016^39^ | 1 | NA | 0 | 0 | Large study that included full population of patients from VA for 1 year. Both mTBI and pain conditions based on presence of ≥1 ICD diagnosis code during study period. | Post-9/11 Veterans receiving VA care in fiscal year 2012.
Lew, 2009^25,*^ | 0 | NA | 1 | 1 | Single site; chart review of all patients assessed for 22 months. No demographics provided. mTBI and general chronic pain defined as clinician documentation in CTBIE chart note but making assumption that post-concussive symptoms associated only with mTBI and not TBI of greater severity. | Post-9/11 Veterans treated at single Level 2 polytrauma clinic.
MacGregor, 2013^49^ | 1 | NA | 0 | 0 | Fairly small multi-site sample but representative of population described. mTBI measurement based on ICD codes and include 1 that would be categorized as ‘moderate’ using VA/DoD common definition. Pain assessment not validated but standard. | Post-9/11 SMs that incur minor-to-moderate deployment injuries as recorded in deployment healthcare database and complete both PDHA and PDHRA within 1-year post-deployment.
Patil, 2011^50,*^ | 0 | NA | 1 | 0 | Consecutive patients from a single VA polytrauma site. mTBI assessed using CTBIE. Headache pain assessed using question on CTBIE and referral/follow-up at Neurology clinic. | Post-9/11 Veterans receiving care in a single VA (polytrauma network site).
Powell, 2015^43^ | 1 | 0 | 1 | 0 | Fairly selective study sample from 1 site (no information on Veterans/SMs who were recruited but did not enroll). mTBI based on clinical interview and consensus among PhD-level psychologists. General pain assessment non-standard. | Post-9/11 Veterans receiving VA care in Boston that would enroll in TRACTS longitudinal study.
Pugh, 2019^7^ | 1 | NA | 1 | 0 | Entire population of VA users. mTBI defined using complex algorithm taking many data sources into account. Pain conditions based on ICD diagnosis codes. | Post-9/11 Veterans who enrolled in and used VA healthcare.
Romesser, 2012^44^ | 0 | NA | 1 | 0 | Fairly selective study sample from 2 polytrauma sites. mTBI and pain assessed from patient self-reported clinical questionnaire; unclear if standardized or validated. | Post-9/11 Veterans assessed in 2 VA polytrauma clinics.
Ruff, 2008^6^ | 1 | NA | 1 | 0 | Fairly small sample of consecutive patients at VA polytrauma clinic. mTBI assessed clinically and defined using VA-DoD standard definition. Headache pain measures were self-reported; focused on deployment-related headaches. | Post-9/11 Veterans seeking care for TBI at VA with blast-related mTBI.
Schwab, 2017^51^ | 1 | 1 | 1 | 1 | Sampled from among SMs with positive mTBI screen at 2 sites; used structured interview to confirm mTBI history. Headache intensity assessed using NSI. Excluded participants with potential symptom exaggeration. Loss to follow-up of 34%; compared responders to non-responders and reported few differences. | Post-9/11 Army soldiers with Iraq/Afghanistan deployment history from 2 military sites.
Seal, 2017^4,*^ | 1 | NA | 1 | 1 | Large study of entire patient population; mTBI assessed using CTBIE; General chronic pain assessed using ICD diagnosis codes, but pain interference assessed using standardized measure from CTBIE. | Post-9/11 Veterans who use VA and completed CTBIE.
Suri, 2017^53,*^ | 1 | 0 | 1 | 1 | Large multi-site sample of VA users that completed CTBIE, considered gold standard assessment for mTBI. Pain measures standard and/or validated (pain interference question from NSI). | Post-9/11 Veterans who use VA and completed CTBIE.
Suri, 2019^52,*^ | 1 | NA | 1 | 0 | Large multi-site population of VA users that completed CTBIE, considered gold standard assessment for mTBI; pain assessed using “pain location” measure on CTBIE. Large proportion of Veterans excluded because of missing data. | Post-9/11 Veterans who use VA and completed CTBIE.
Theeler, 2012^54^ | 0 | 0 | 1 | 0 | Participants from 1 site; enrolled based on positive mTBI screen but presumed confirmed in TBI clinic. Demographics not reported. Unknown if pain measure was standardized or validated. | Post-9/11 SMs who had a deployment-related concussion in Iraq or Afghanistan.
Tsao, 2017^55^ | 1 | 0 | 0 | 0 | Sample of post-deployment SMs from 3 sites; unclear what proportion of recruited SMs participated and how responders differed from non-responders. mTBI assessed using screening questions (VA-DoD common definition). Headache pain assessed using non-standardized/validated item(s) on questionnaire. | Post-9/11 male Marines returning from Iraq/Afghanistan deployments at 1 of 3 sites in the US.
Vanderploeg, 2009^56^ | 1 | 0 | 0 | 0 | Random-sample and in-person assessments. No description of non-respondents. Non-standard measures of mTBI and pain. | Male Vietnam-era Army Veterans.
Walker, 2018^57^,^†^ | 1 | 0 | 1 | 1 | Fairly selective study sample from 4 sites (no information on Veterans/SMs who were recruited but did not enroll). Standardized and validated measures of mTBI and pain were used. | Post-9/11 Veterans/SMs with combat exposure enrolled in a comprehensive longitudinal study.
Webb, 2015^58^ | 1 | NA | 0 | 0 | Entire population of Military Health System users across multiple sites. mTBI defined using CDC-recommended series of ICD diagnosis codes. Headache and migraine pain based on ICD diagnosis codes. | Post-9/11 Air Force SMs who used Military Health System between 2001 and 2008.
Wilk, 2010^60^ | 1 | 0 | 0 | 1 | Survey from single-site with 57% response rate, no information on non-respondents. mTBI assessed using screening questions. Pain measures assessed using validated instrument (PHQ-15). Bivariable analyses only in blast/non-blast comparisons. | Post-9/11 Army SMs shortly after return from high-combat deployment.
Wilk, 2012^59^ | 1 | 0 | 0 | 1 | Survey from single site with 73% response rate, no information on non-respondents. mTBI assessed using screening questions. Pain measures assessed using validated instrument (PHQ-15). | Post-9/11 Army SMs shortly after return from combat deployment.

* Study based on VA Comprehensive TBI Evaluation (CTBIE) data.

† Chronic Effects of Neurotrauma Consortium (CENC) longitudinal cohort study.

Abbreviations: CDC=Centers for Disease Control and Prevention; CTBIE=Clinical TBI Evaluation; DoD=Department of Defense; ICD=International Classification of Diseases; mTBI=Mild Traumatic Brain Injury; SMs=Servicemembers; VA=Veterans Affairs; VISN=Veterans Integrated Services Network; PTSD=Posttraumatic stress disorder; NA=Not applicable

## Quality Assessment Criteria

1. Representativeness of the sample:
  1=Truly representative of the target population
  1=Somewhat representative of the target population
  0=Selected subset of Veterans/SMs
  0=No
2. Non-respondents/non-enrolled:
  Enter 0 or 1:
  1=Comparability between respondent and non-respondent characteristics is established; response rate is satisfactory
  0=Comparability between respondents and non-respondents is unsatisfactory; response rate is unsatisfactory
  0=No description of the characteristics of the responders versus non-responders; no description of response rate
  NA=EHR studies (patient does not opt in versus opt out)
3. Were objective, standard criteria used for measurement of mTBI?
  Enter 0 or 1:
  1=Validated measures (eg any that uses VA/DoD common definition with clinical interview)
  0=Administrative codes
  0=Non-validated (eg, reported concussion, self-report, initial screen)
4. Were standard, validated criteria used for measurement of chronic pain?
  Enter 0 or 1:
  a) All measures standard and/or validated? (if some are validated and some are not, note which get 1 or 0)
  1=yes
  0=no, self-report measure; not validated for chronic pain measurement
  0=no, proxy measure used (eg, opioid medication use)