# APPENDIX B STUDY SELECTION

## Inclusion/Exclusion Criteria for Full Text Review

VA-ESP Chronic Pain in Veterans and Servicemembers with a History of Mild Traumatic Brain Injury

1. Language: Is the full text of the article in English?
  - Yes → Proceed to #2
  - No → Code X1. STOP
2. Publication type: Is this a published study (exclude: dissertations, conference abstracts, protocols, unpublished results, letters, reviews, etc)?
  - Yes → Proceed to #3
  - No → Code X2. Add code B (example: X2 – B) if retaining for background/discussion.
  - STOP
3. Population: Does the study include adult Veterans or Servicemembers with chronic pain [underlined: and] a history of mTBI?
  [underlined: Definitions]: Pain: Include headaches/migraines. Chronic>3 months. Assume chronic unless explicitly says acute. mTBI: If mixed TBI population (eg mild, mod, and or severe), only include if mTBI results are reported separately. Include concussion. “Post-concussive symptoms” okay only if there’s confirmation of mTBI or concussion that caused the symptoms (eg, a sample of recently returned Vets who complete the NSI and score 20 or higher does NOT qualify unless the study specifies that they all had a concussion or mTBI).
  - Yes → Proceed to #4
  - No → Code X3. Add code B if retaining for background/discussion. STOP
4. Population: Is this a U.S. population?
  - Yes → Proceed to #5
  - No, they’re international → Does it appear to address benefits and harms of interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI (KQ3)?
    - Yes → Proceed to #5
    - No → Code X3. STOP
5. Intervention: Is the study examining pharmacologic, nonpharmacologic, or complementary and integrative health interventions to treat chronic pain in Veterans or Servicemembers with a history of mTBI (KQ3)?
  - Yes → Proceed to #8
  - No, not a treatment/intervention study → Proceed to #6.
  - No, not treating chronic pain → Code X5
6. Study design: Does the study report prevalence of chronic pain in the population of interest?
  - Yes, reports prevalence → Proceed to #7
  - No → Code X6
7. KQ2: Does this study report the prevalence of suicide-related outcomes (including suicide, suicidal ideation/intent/plan, and suicidal self-directed harm) in Veterans or Servicemembers with chronic pain and a history of mTBI?
  - Yes → Code 1 for KQ2. Proceed to #8
  - No → Proceed to #8
8. Study design: Is this an RCT, NRCT, cohort, prospective, or retrospective study (Exclude: Case studies/reports, cross-sectional, modeling studies)?
  - Yes → Proceed to #9
  - No → but it does have at least 1 KQ coded. STOP.
  - No → and it has no previous code. Code X6
9. Comparators: Is the comparator population 1 of the following: Placebo, active comparator, usual care, wait-list control, pre-post? Note: KQ1 and 1c do not require comparator, proceed to #11.
  - Yes → Proceed to #10
  - No → Code X4
10. Outcomes: does the study report benefits (eg reduced pain, mental health diagnosis/symptoms, opioid use; better QOL, functioning, treatment adherence) or harms (eg AEs, SAEs, withdrawals due to AEs) outcomes for chronic pain in Veterans/Servicemembers with history of mTBI measured by a validated tool?
  - Yes → Code 1 for KQ3. STOP
  - No → Code X5. STOP

Codes Key:

- X1: Not English-language
- X2: Excluded publication type
- X3: Excluded population
- X4: Excluded comparator
- X5: No outcomes of interest
- X6: Excluded study design