# APPENDIX A SEARCH STRATEGIES

## Ovid MEDLINE(R) ALL 1946 to March 04, 2020

Date searched: March 5, 2020

1 | Brain Concussion/ or Brain Contusion/ or Brain Hemorrhage, Traumatic/ or Brain Injuries, Traumatic/ or Brain Stem Hemorrhage, Traumatic/ or Cerebral Hemorrhage, Traumatic/ or Chronic Traumatic Encephalopathy/ or Contrecoup Injury/ or Craniocerebral Trauma/ or Head Injuries, Closed/ or Intracranial Hemorrhage, Traumatic/ or Post-concussion Syndrome/ or Blast Injuries/
2 | (TBI or mTBI or bTBI or ((trauma or traumas or traumatic or posttraumatic or posttraumatic) adj2 (brain or crania* or cranio* or cerebr* or cortex or cortical or head*)) or concussion or concussions or concussive or contrecoup or coup-contrecoup or “minor brain” or “minor head” or postconcussion or postconcussive or post-concussion or postconcussive).ti,ab,kf.
3 | or/1–2
4 | Arthritis/ or Arthritis, Psoriatic/ or exp Arthritis, Rheumatoid/ or Back Pain/ or Chronic Pain/ or exp Chondrocalcinosis/ or Complex Regional Pain Syndromes/ or exp Facial Neuralgia/ or Fatigue Syndrome, Chronic/ or Femoral Neuropathy/ or Fibromyalgia/ or exp Gout/ or Headache/ or Headache Disorders/ or Headache Disorders, Primary/ or Headache Disorders, Secondary/ or Low Back Pain/ or exp Migraine Disorders/ or Musculoskeletal Pain/ or Myalgia/ or Myofascial Pain Syndromes/ or Neck Pain/ or exp Neuralgia/ or exp Osteoarthritis/ or Pain, Intractable/ or Phantom Limb/ or PostTraumatic Headache/ or Radial Neuropathy/ or exp Spondylosis/ or Tension-type Headache/ or exp Trigeminal Autonomic Cephalalgias/ or Vascular Headaches/
5 | (exp Pain/ or pain.hw.) and (arthrit* or “complex regional pain” or CRPS or fibromyalgia or gout or headache* or “low back” or migrain* or myalgia or neuralgia or neuropath* or nocicept* or osteoarthrit* or osteo-arthrit* or “phantom limb” or “reflex sympathetic dystrophy” or spondylosis or (central* adj2 (pain* or sensit*))).ti,ab,kf.
6 | (arthrit* or “chronic fatigue” or “complex regional pain” or CRPS or fibromyalgia or gout or headache* or migrain* or myalgia or neuralgia or neuropath* or nocicept* or osteoarthrit* or osteo-arthrit* or “phantom limb” or “polytrauma clinical triad” or “reflex sympathetic dystrophy” or spondylosis or (central* adj2 (pain* or sensit*)) or pain).ti,ab,kf.
7 | or/4–6
8 | and/3,7
9 | 8 not ((exp Animals/ not Humans/) or ("animal model*" or cat or cats or dog or dogs or mice or mouse or rat or rats or rodent).ti.)
10 | 9 not (((Adolescent/ or exp Child/ or exp Infant/) not exp Adult/) or (adolescent or adolescents or adolescence or child or children or childhood or juvenile or pediatric or paediatric or preschool or pre-school or school-age or teen or teens or teenager or teenagers or youth or youths).ti.)
11 | 10 not case reports.pt.
12 | limit 11 to english language

Veteran/ Servicemember filter terms used:

13 | exp Veterans/ or exp “United States Department of Veterans Affairs”/ or exp Veterans Disability Claims/ or exp Veterans Health/ or Veterans Health Services/ or exp Hospitals, Veterans/ or Aerospace Medicine/ or Armed Conflicts/ or Hospitals, Military/ or Military Health/ or Military Personnel/ or Military Medicine/ or Military Nursing/ or Military Psychiatry/ or exp Naval Medicine/ or Psychology, Military/ or Gulf War/ or Vietnam Conflict/ or World War ii/ or Afghan Campaign 2001-/ or Iraq War, 2003–2011/ or War/ or exp “Warfare and Armed Conflicts”/ or War-Related Injuries/ or War Exposure/ or Warfare/ or Biological Warfare/ or Chemical Warfare/ or Nuclear Warfare/ or Psychological Warfare/
14 | (“active duty” or “armed forces” or “armed service*” or “coast guard*” or military or “air force” or army or “defense force*” or “marine corps” or marines or “national guard*” or (navy not bean) or naval or “security force*” or air-men or air-man or airmen or airman or corpsman or corpsmen or guardsman or guardsmen or infantry* or medic or medics or reservist* or sailor* or soldier* or servicemember* or service-member* or “special forces” or submariner* or troops or battle* or combat or deployed or deployment* or post-deployment* or postdeployment* or veteran* or VAMC or Veterans Administration Medical Center* or VHA or Veterans* Health Administration or war or wars or warfare or war-fighter* or warfighter* or war-related).tw,kf.
15 | (((VA or Veteran Affairs or Veterans’ Affairs or Veterans Affairs or Veterans Administration) adj4 (health care system or healthcare system or medical center or hospital)) or VAMC or Veteran Affairs or Veterans’ Affairs or Veterans Affairs or Veterans Administration Medical Center or Veterans’ Affairs Medical Center or Veterans Affairs Medical Center or Veterans Health Administration or QUERI or “Mental Health Quality Enhancement Research Initiative” or HSR&D or “Center of Innovation for Veteran-Centered Value-Driven Care” or “Evidence-based Synthesis Program” or ((Veteran* or VA) adj5 (Office of Research and Development)) or “Center for Health Equity Research and Promotion” or “Women’s Health Research Network” or “Cooperative Studies Program” or “Million Veteran Program”).in.
16 | (military or army or soldier* or navy* or veteran or veterans).jw.
17 | or/13–16
18 | and/12,17

## CINAHL Plus with Full Text (EBSCOHost)

Date searched: February 10, 2020

S1 MH Brain Concussion OR Brain Contusions OR Brain Injuries OR Chronic Traumatic Encephalopathy OR Head Injuries (32,064)

S2 TI ( TBI OR mTBI OR bTBI OR ((trauma OR traumas OR traumatic OR posttraumatic OR post-traumatic) N2 (brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head*)) OR concussion OR concussions OR concussive OR contrecoup OR coup-contrecoup OR “minor brain” OR “minor head” OR postconcussion OR postconcussive OR post-concussion OR post-concussive ) OR AB ( TBI OR mTBI OR bTBI OR ((trauma OR traumas OR traumatic OR posttraumatic OR post-traumatic) N2 (brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head*)) OR concussion OR concussions OR concussive OR contrecoup OR coupcontrecoup OR “minor brain” OR “minor head” OR postconcussion OR postconcussive OR post-concussion OR post-concussive ) (22,788)

S3 S1 OR S2 (38,328)

S4 MH Arthritis OR Arthritis, Psoriatic OR Arthritis, Rheumatoid OR Back Pain OR Chondrocalcinosis OR Chronic Pain OR Cluster Headache OR Complex Regional Pain Syndromes OR Facial Pain OR Fatigue Syndrome, Chronic OR Gout OR Headache OR Headache, Primary OR Headache, Secondary OR Low Back Pain OR Migraine OR Muscle Pain OR Myofascial Pain Syndromes OR Neck Pain OR Neuralgia OR Osteoarthritis OR Phantom Limb OR Phantom Pain OR Spondylosis OR Tension Headache OR Trigeminal Autonomic Cephalalgias OR Vascular Headache (127,543)

S5 TI ( arthrit* OR chondrocalcinosis OR “chronic fatigue” OR “complex regional pain” OR CRPS OR fibromyalgia OR gout OR headache* OR “low back” OR migrain* OR musculoskeletal OR musculo-skeletal OR myalgia OR neuralgia OR neuropath* OR nocicept* OR osteoarthrit* OR osteo-arthrit* OR “phantom limb” OR “reflex sympathetic dystrophy” OR spondylosis OR (central* N2 (pain* OR sensit*)) OR ((chronic OR intractable OR long-term OR longer-term OR noncancer OR non-cancer OR nonmalignant OR non-malignant OR persistent* OR refractory) N3 pain) ) OR AB ( arthrit* OR chondrocalcinosis OR “chronic fatigue” OR “complex regional pain” OR CRPS OR fibromyalgia OR gout OR headache* OR “low back” OR migrain* OR musculoskeletal OR musculo-skeletal OR myalgia OR neuralgia OR neuropath* OR nocicept* OR osteoarthrit* OR osteo-arthrit* OR “phantom limb” OR “reflex sympathetic dystrophy” OR spondylosis OR (central* N2 (pain* OR sensit*)) OR ((chronic OR intractable OR long-term OR longer-term OR noncancer OR non-cancer OR nonmalignant OR nonmalignant OR persistent* OR refractory) N3 pain) ) (198,244)

S6 S4 OR S5 (239,755)

S7 S3 AND S6 Limiters - English Language; Human; Age Groups: Adult: 19–44 years, Middle Aged: 45–64 years, Aged: 65+ years, Aged, 80 and over, All Adult (435)

## PsycINFO (Ovid) 1806 to February Week 1 2020

Date searched: February 7, 2020

1 Traumatic Brain Injury/ or Brain Concussion/ (19109)

2 (TBI or mTBI or bTBI or ((trauma or traumas or traumatic or posttraumatic or post-traumatic) adj2 (brain or crania* or cranio* or cerebr* or cortex or cortical or head*)) or concussion or concussions or concussive or contrecoup or coup-contrecoup or “minor brain” or “minor head” or postconcussion or postconcussive or post-concussion or post-concussive).ti,ab. (21754) 3 or/1–2 (25224)

4 Arthritis/ or Rheumatoid Arthritis/ or Back Pain/ or Chronic Pain/ or “Complex Regional Pain Syndrome (Type I)”/ or Chronic Fatigue Syndrome/ or Fibromyalgia/ or Headache/ or Migraine Headache/ or Myofascial Pain/ or Muscle Contraction Headache/ or Neuropathy/ or Neuropathic Pain/ or Phantom Limbs/ or Trigeminal Neuralgia/ (43617)

5 (arthrit* or chondrocalcinosis or “chronic fatigue” or “complex regional pain” or CRPS or fibromyalgia or gout or headache* or “low back” or migrain* or musculoskeletal or musculo-skeletal or myalgia or neuralgia or neuropath* or nocicept* or osteoarthrit* or osteo-arthrit* or “phantom limb” or “reflex sympathetic dystrophy” or spondylosis or (central* adj2 (pain* or sensit*)) or ((chronic or intractable or long-term or longer-term or noncancer or non-cancer or nonmalignant or non-malignant or persist?nt* or refractory) adj3 pain)).ti,ab. (86759)

6 or/4–5 (89596)

7 and/3,6 (1680)

8 limit 7 to animal (246)

9 7 not 8 (1434)

10 limit 9 to ("300 adulthood<age 18 yrs and older>" or 320 young adulthood<age 18 to 29 yrs>or 340 thirties<age 30 to 39 yrs>or 360 middle age<age 40 to 64 yrs>or “380 aged<age 65 yrs and older>” or “390 very old<age 85 yrs and older>”) (711)

11 9 not (adolescent or adolescents or adolescence or child or children or childhood or juvenile or pediatric or paediatric or preschool or pre-school or school-age or teen or teens or teenager or teenagers or youth or youths).ti. (1327)

12 or/10–11 (1355)

13 limit 12 to ("0200 clinical case study" or 1400 nonclinical case study) (127)

14 12 not 13 (1228)

15 limit 14 to english language (1180)

## EBM Reviews (Ovid) - Cochrane Central Register of Controlled Trials (December 2019) and Cochrane Database of Systematic Reviews (2005 to February 4, 2020)

Date searched: February 7, 2020

1 (TBI or mTBI or bTBI or ((trauma or traumas or traumatic or posttraumatic or post-traumatic) adj2 (brain or crania* or cranio* or cerebr* or cortex or cortical or head*)) or concussion or concussions or concussive or contrecoup or coup-contrecoup or “minor brain” or “minor head” or postconcussion or postconcussive or post-concussion or post-concussive).ti,ab. (5149)

2 (arthrit* or “chronic fatigue” or “complex regional pain” or CRPS or fibromyalgia or gout or headache* or “low back” or migrain* or myalgia or neuralgia or neuropath* or nocicept* or osteoarthrit* or osteo-arthrit* or “phantom limb” or “reflex sympathetic dystrophy” or spondylosis or (central* adj2 (pain* or sensit*)) or ((chronic or intractable or long-term or longer-term or noncancer or non-cancer or nonmalignant or non-malignant or persist?nt* or refractory) adj3 pain)).ti,ab. (87910)

3 and/1–2 (297)

4 3 not ("animal model*" or cat or cats or dog or dogs or mice or mouse or rat or rats or rodent).ti. (297)

5 4 not (adolescent or adolescents or adolescence or child or children or childhood or juvenile or pediatric or paediatric or preschool or pre-school or school-age or teen or teens or teenager or teenagers or youth or youths).ti. (273)

## Scopus

Date searched: February 10, 2020

( TITLE-ABS-KEY ( tbi OR mtbi OR btbi OR ( ( trauma* OR posttraumatic OR post-traumatic ) W/2 ( brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head* ) ) OR concussion* OR concussive OR contrecoup OR coup-contrecoup OR “minor brain” OR “minor head” OR postconcuss* ) ) AND ( ( TITLE-ABS-KEY ( arthrit* OR “chronic fatigue” OR “complex regional pain” OR crps OR fibromyalgia OR gout OR headache* OR migrain* OR myalgia OR neuralgia OR neuropath* OR nocicept* OR osteoarthrit* OR osteo-arthrit* OR “phantom limb” ) OR TITLE-ABS-KEY ( “reflex sympathetic dystrophy” OR spondylosis OR ( central* W/2 ( pain* OR sensit* ) ) OR ( ( chronic OR intractable OR long-term OR longer-term OR noncancer OR non-cancer OR nonmalignant OR non-malignant OR persist?nt* OR refractory ) W/3 pain ) ) ) ) AND ( LIMIT-TO ( DOCTYPE , “cp” ) ) AND ( LIMIT-TO ( LANGUAGE , “English” ) ) (155)

## Epistemonikos

Date searched: February 10, 2020 advanced_title_en:(TBI OR mTBI OR bTBI OR (trauma OR traumatic OR posttraumatic OR post-traumatic ) AND ( brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head* ) OR concussion* OR concussive OR “minor brain” OR “minor head” OR postconcuss*) AND advanced_title_en:(arthritis OR chronic OR “complex regional” OR crps OR fibromyalgia OR gout OR headache OR migraine OR myalgia OR neuralgia OR neuropathy OR nociceptive OR osteoarthritis OR osteo-arthritis OR phantom limb OR spondylosis OR centralized pain OR central sensitization OR intractable OR long-term OR longer-term OR noncancer OR non-cancer OR nonmalignant OR non-malignant OR persistent OR refractory) NOT advanced_title_en:(adolescent OR adolescents OR adolescence OR child OR children OR childhood OR juvenile OR pediatric OR paediatric OR preschool OR pre-school OR school-age OR teen OR teens OR teenager OR teenagers OR youth OR youths) [Filters: classification=systematic-review, protocol=no, cochrane=missing, pmc=without] (109)

## ClinicalTrials.gov

Date searched: February 10, 2020

( arthritis OR chronic fatigue OR complex regional pain OR crps OR fibromyalgia OR gout OR headache OR migraine OR myalgia OR neuralgia OR neuropathy OR nociceptive OR osteoarthrits OR osteo-arthritis OR phantom limb OR post-traumatic headache OR reflex sympathetic dystrophy OR spondylosis OR central pain OR centralized pain OR centralized sensitivity OR chronic pain OR intractable pain OR long-term pain OR longer-term pain OR noncancer pain OR non-cancer pain OR nonmalignant pain OR non-malignant pain OR persistent pain OR refractory pain ) | TBI OR mTBI OR bTBI OR (trauma* OR posttraumatic OR post-traumatic ) AND ( brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head*) OR concussion* OR concussive OR contrecoup OR coup-contrecoup OR EXPAND[Concept] “minor brain” OR EXPAND[Concept] “minor head” OR postconcuss* | Adult, Older Adult (210)

## WHO ICTRP

Date searched: February 10, 2020

Title=TBI OR mTBI OR bTBI OR (trauma OR traumatic OR posttraumatic OR post-traumatic) AND (brain OR crania* OR cranio* OR cerebr* OR cortex OR cortical OR head*) OR concussion* OR concussive OR “minor brain” OR “minor head" OR postconcuss* Condition=arthritis OR chronic OR “complex regional” OR crps OR fibromyalgia OR gout OR headache OR migraine OR myalgia OR neuralgia OR neuropathy OR nociceptive OR osteoarthritis OR osteo-arthritis OR phantom limb OR reflex sympathetic dystrophy OR spondylosis OR centralized pain OR central sensitization OR intractable OR long-term OR longer-term OR noncancer OR non-cancer OR nonmalignant OR non-malignant OR persistent OR refractory (without synonyms checked) Recruitment status=ALL (140)

## Google Scholar

Date searched: February 10, 2020

2 separate searches were conducted, reviewed first 10 pages of results for each (TBI OR mTBI OR “traumatic brain” OR concussion OR “minor brain” OR “minor head” OR postconcuss*) AND (pain OR central sensitization OR intractable OR long-term OR noncancer OR non-cancer OR nonmalignant OR non-malignant OR persistent OR refractory) (TBI OR mTBI OR “traumatic brain” OR concussion OR “minor brain” OR “minor head” OR postconcussion) AND (chronic OR intractable OR long-term OR persistent OR refractory) AND (treatment OR management OR intervention) (10)