# REFERENCES

1 Coleman EA, Berenson RA. Lost in transition: challenges and opportunities for improving the quality of transitional care. Ann Intern Med. 2004;141(7):533–536.15466770
2 Gadbois EA, Tyler DA, Shield R, . Lost in Transition: a Qualitative Study of Patients Discharged from Hospital to Skilled Nursing Facility. J Gen Intern Med. 2019;34(1):102–109.30338471
3 Harrison A, Verhoef M. Understanding coordination of care from the consumer’s perspective in a regional health system. Health Serv Res. 2002;37(4):1031–1054.12236382
4 Montgomery JE, Irish JT, Wilson IB, . Primary care experiences of medicare beneficiaries, 1998 to 2000. J Gen Intern Med. 2004;19(10):991–998.15482550
5 McDonald K, Schultz E, Albin L, . Care Coordination Atlas Version 4 (AHRQ Publication No. 14-0037-EF). Rockville, MD: Agency for Healthcare Research and Quality;2014.
6 Shojania KG, Wachter RM, Owens DK, . Closing the quality gap: a critical analysis of quality improvement strategies. Care Coordination. 2007;7.
7 Peterson K, Anderson J, Bourne D, Boundy E. Scoping Brief: Care Coordination Theoretical Models and Frameworks. VA ESP Project #09-199;2018.
8 Weaver SJ, Che XX, Petersen LA, Hysong SJ. Unpacking Care Coordination Through a Multiteam System Lens. Med Care. 2018;56(3):247–259.29356720
9 Greenstone CL, Peppiatt J, Cunningham K, . Standardizing Care Coordination Within the Department of Veterans Affairs. J Gen Intern Med. 2019;34:(Suppl 1):4–6.31098969
10 Lemieux-Charles L, McGuire WL. What do we know about health care team effectiveness? A review of the literature. Med Care Res Rev. 2006;63(3):263–300.16651394
11 Valentijn PP, Schepman SM, Opheij W, Bruijnzeels MA. Understanding integrated care: a comprehensive conceptual framework based on the integrative functions of primary care. Int J Integr Care. 2013;13:e010.23687482
12 Gittell JH, Weiss L. Coordination networks within and across organizations: A multi-level Framework. J Manag Stud. 2004;41(1):127–153.
13 Rockers PC, Rottingen JA, Shemilt I, Tugwell P, Barnighausen T. Inclusion of quasi-experimental studies in systematic reviews of health systems research. Health Policy. 2015;119(4):511–521.25776033
14 Shea BJ, Reeves BC, Wells G, . AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. 2017;358:j4008.28935701
15 Baker JM, Grant RW, Gopalan A. A systematic review of care management interventions targeting multimorbidity and high care utilization. BMC Health Serv Res. 2018;18(1):65.29382327
16 Bleich SN, Sherrod C, Chiang A, . Systematic Review of Programs Treating High-Need and High-Cost People With Multiple Chronic Diseases or Disabilities in the United States, 2008-2014. Prev Chronic Dis. 2015;12:E197.26564013
17 De Pourcq K, Meijboom B, Trybou J, Mortier E, Eeckloo K. The role of hospitals in bridging the care continuum: a systematic review of coordination of care and follow-up for adults with chronic conditions. BMC Health Serv Res. 2017;17(1):550.28793893
18 Di Mauro R, Di Silvio V, Bosco P, Laquintana D, Galazzi A. Case management programs in emergency department to reduce frequent user visits: a systematic review. Acta Biomed. 2019;90(6-S):34–40.31292413
19 Hudon C, Chouinard MC, Pluye P, . Characteristics of Case Management in Primary Care Associated With Positive Outcomes for Frequent Users of Health Care: A Systematic Review. Ann Fam Med. 2019;17(5):448–458.31501208
20 Iovan S, Lantz PM, Allan K, Abir M. Interventions to Decrease Use in Prehospital and Emergency Care Settings Among Super-Utilizers in the United States: A Systematic Review. Med Care Res Rev. 2020;77(2):99–111.31027455
21 Joo JY, Liu MF. Case management effectiveness in reducing hospital use: a systematic review. Int Nurs Rev. 2017;64(2):296–308.27861853
22 Le Berre M, Maimon G, Sourial N, Gueriton M, Vedel I. Impact of Transitional Care Services for Chronically Ill Older Patients: A Systematic Evidence Review. J Am Geriatr Soc. 2017;65(7):1597–1608.28403508
23 Moe J, Kirkland SW, Rawe E, . Effectiveness of Interventions to Decrease Emergency Department Visits by Adult Frequent Users: A Systematic Review. Acad Emerg Med. 2017;24(1):40–52.27473387
24 Raven MC, Kushel M, Ko MJ, Penko J, Bindman AB. The Effectiveness of Emergency Department Visit Reduction Programs: A Systematic Review. Ann Emerg Med. 2016;68(4):467–483 e415.27287549
25 Smith SM, Wallace E, O’Dowd T, Fortin M. Interventions for improving outcomes in patients with multimorbidity in primary care and community settings. Cochrane Database Syst Rev. 2016;3:CD006560.26976529
26 Soril LJ, Leggett LE, Lorenzetti DL, Noseworthy TW, Clement FM. Reducing frequent visits to the emergency department: a systematic review of interventions. PLoS ONE. 2015;10(4):e0123660.25874866
27 Van der Elst M, Schoenmakers B, Duppen D, . Interventions for frail community-dwelling older adults have no significant effect on adverse outcomes: a systematic review and meta-analysis. BMC Geriatr. 2018;18(1):249.30342479
28 Weeks LE, Macdonald M, Martin-Misener R, . The impact of transitional care programs on health services utilization in community-dwelling older adults: a systematic review. JBI Database System Rev Implement Rep. 2018;16(2):345–384.
29 Edwards ST, Peterson K, Chan B, Anderson J, Helfand M. Effectiveness of Intensive Primary Care Interventions: A Systematic Review. J Gen Intern Med. 2017;32(12):1377–1386.28924747
30 Totten AM, White-Chu EF, Wasson N, . Home-based primary care interventions. Rockville, MD: Agency for Healthcare Research and Quality; 02 2016.
31 Balaban RB, Galbraith AA, Burns ME, Vialle-Valentin CE, Larochelle MR, Ross-Degnan D. A patient navigator intervention to reduce hospital readmissions among high-risk safety-net patients: a randomized controlled trial. J Gen Intern Med. 2015;30(7):907–915.25617166
32 Boult C, Reider L, Leff B, . The effect of guided care teams on the use of health services: results from a cluster-randomized controlled trial. Arch Intern Med. 2011;171(5):460–466.21403043
33 Coleman EA, Grothaus LC, Sandhu N, Wagner EH. Chronic care clinics: a randomized controlled trial of a new model of primary care for frail older adults. J Am Geriatr Soc. 1999;47(7):775–783.10404919
34 Coleman EA, Parry C, Chalmers S, Min SJ. The care transitions intervention: results of a randomized controlled trial. Arch Intern Med. 2006;166(17):1822–1828.17000937
35 Hughes SL, Cummings J, Weaver F, Manheim LM, Conrad KJ, Nash K. A randomized trial of Veterans Administration home care for severely disabled veterans. Med Care. 1990;28(2):135–145.2153881
36 Hughes SL, Weaver FM, Giobbie-Hurder A, . Effectiveness of team-managed home-based primary care: a randomized multicenter trial. JAMA. 2000;284(22):2877–2885.11147984
37 Lin MP, Blanchfield BB, Kakoza RM, . ED-based care coordination reduces costs for frequent ED users. Am J Manag Care. 2017;23(12):762–766.29261242
38 Linden A, Butterworth S. A comprehensive hospital-based intervention to reduce readmissions for chronically ill patients: a randomized controlled trial. Am J Manag Care. 2014;20(10):783–792.25365681
39 Naylor MD, Brooten D, Campbell R, . Comprehensive discharge planning and home follow-up of hospitalized elders: a randomized clinical trial. JAMA. 1999;281(7):613–620.10029122
40 Newcomer R, Maravilla V, Faculjak P, Graves MT. Outcomes of preventive case management among high-risk elderly in three medical groups: a randomized clinical trial. Eval Health Prof. 2004;27(4):323–348.15492046
41 Parry C, Min S-J, Chugh A, Chalmers S, Coleman EA. Further application of the care transitions intervention: results of a randomized controlled trial conducted in a fee-for-service setting. Home Health Care Serv Q. 2009;28(2-3):84–99.20182958
42 Peikes D, Chen A, Schore J, Brown R. Effects of care coordination on hospitalization, quality of care, and health care expenditures among Medicare beneficiaries: 15 randomized trials. JAMA. 2009;301(6):603–618.19211468
43 Shannon GR, Wilber KH, Allen D. Reductions in costly healthcare service utilization: findings from the Care Advocate Program. J Am Geriatr Soc. 2006;54(7):1102–1107.16866682
44 Shumway M, Boccellari A, O’Brien K, Okin RL. Cost-effectiveness of clinical case management for ED frequent users: results of a randomized trial. Am J Emerg Med. 2008;26(2):155–164.18272094
45 Sledge WH, Brown KE, Levine JM, . A randomized trial of primary intensive care to reduce hospital admissions in patients with high utilization of inpatient services. Dis Manag. 2006;9(6):328–338.17115880
46 Zulman DM, Pal Chee C, Ezeji-Okoye SC, . Effect of an Intensive Outpatient Program to Augment Primary Care for High-Need Veterans Affairs Patients: A Randomized Clinical Trial. JAMA Intern Med. 2017;177(2):166–175.28027338
47 Finkelstein A, Zhou A, Taubman S, Doyle J. Health Care Hotspotting - A Randomized, Controlled Trial. N Engl J Med. 2020;382(2):152–162.31914242
48 Yoon J, Chang E, Rubenstein LV, . Impact of Primary Care Intensive Management on High-Risk Veterans’ Costs and Utilization: A Randomized Quality Improvement Trial. Ann Intern Med. 2018;168(12):846–854.29868706
49 Capp R, Misky GJ, Lindrooth RC, . Coordination program reduced acute care use and increased primary care visits among frequent emergency care users. Health Affairs. 2017;36(10):1705–1711.28971914
50 Crane S, Collins L, Hall J, Rochester D, Patch S. Reducing utilization by uninsured frequent users of the emergency department: combining case management and drop-in group medical appointments. J Am Board Fam Med. 2012;25(2):184–191.22403199
51 Gardner R, Li Q, Baier RR, Butterfield K, Coleman EA, Gravenstein S. Is implementation of the care transitions intervention associated with cost avoidance after hospital discharge? J Gen Intern Med. 2014;29(6):878–884.24590737
52 Hamar B, Rula EY, Wells AR, Coberley C, Pope JE, Varga D. Impact of a scalable care transitions program for readmission avoidance. Am J Manag Care. 2016;22(1):28–34.26799122
53 Meret-Hanke LA. Effects of the program of all-inclusive care for the elderly on hospital use. The Gerontologist. 2011;51(6):774–785.21737398
54 Schubert CC, Myers LJ, Allen K, Counsell SR. Implementing Geriatric Resources for Assessment and Care of Elders Team Care in a Veterans Affairs Medical Center: Lessons Learned and Effects Observed. J Am Geriatr Soc. 2016;64(7):1503–1509.27305428
55 Shah R, Chen C, O’Rourke S, Lee M, Mohanty SA, Abraham J. Evaluation of care management for the uninsured. Med Care. 2011;49(2):166–171.21206292
56 Sommers LS, Marton KI, Barbaccia JC, Randolph J. Physician, nurse, and social worker collaboration in primary care for chronically ill seniors. Arch Intern Med. 2000;160(12):1825–1833.10871977
57 Weerahandi H, Basso Lipani M, Kalman J, . Effects of a Psychosocial Transitional Care Model on Hospitalizations and Cost of Care for High Utilizers. Soc Work Health Care. 2015;54(6):485–498.26186421
58 Brown R, Peikes D, Chen A, Ng J, Schore J, Soh C. The evaluation of the Medicare coordinated care demonstration: Findings for the first two years. Paper presented at: Second Report to Congress. Mathematica Policy Research, Inc. Princeton, NJ2007.
59 Parry C, Kramer HM, Coleman EA. A qualitative exploration of a patient-centered coaching intervention to improve care transitions in chronically ill older adults. Home Health Care Serv Q. 2006;25(3-4):39–53.17062510
60 Watkins K, Smith B, Paddock S, . Veterans Health Administration Mental Health Program Evaluation Capstone Report. In: RAND Corporation; 2011.
61 Wray LO, Szymanski BR, Kearney LK, McCarthy JF. Implementation of primary care-mental health integration services in the Veterans Health Administration: program activity and associations with engagement in specialty mental health services. J Clin Psychol Med Settings. 2012;19(1):105–116.22383016
62 Fulton J, Williams J, LeBlanc T, . Integrated Outpatient Palliative Care in Oncology. VA ESP;2017.
63 Curran GM, Bauer M, Mittman B, Pyne JM, Stetler C. Effectiveness-implementation hybrid designs: combining elements of clinical effectiveness and implementation research to enhance public health impact. Med Care. 2012;50(3):217–226.22310560
64 Damschroder LJ, Aron DC, Keith RE, Kirsh SR, Alexander JA, Lowery JC. Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. 2009;4(1):50.19664226
65 Rabin BA, McCreight M, Battaglia C, . Systematic, Multimethod Assessment of Adaptations Across Four Diverse Health Systems Interventions. Front Public Health. 2018;6:102.29686983
66 Glasgow RE, Vogt TM, Boles SM. Evaluating the public health impact of health promotion interventions: the RE-AIM framework. Am J Public Health. 1999;89(9):1322–1327.10474547