# ACKNOWLEDGMENTS

This topic was developed in response to a nomination from the Office of Nursing Services and the Office of Care Management and Social Work Services to support the Coordinated Care and Integrated Case Management (CC&ICM) Initiative. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Lisa Perla, MSN, FNP, CNRN, CRRN
  Co-lead, Data Management and Research Workgroup
  Coordinated Care and Integrated Case Management Initiative
- Janet Belisle, MHA, RHIA, FACHE
  Co-lead, Data Management and Research Workgroup
  Care Management and Social Work Services
- Jimmy Boerschmann, RN, BSN, MSHC
  Co-lead, Data Management and Research Workgroup
  Office of Nursing Services
- Elizabeth Sprinkle, LCSW, C-ASWCM, MVF-ASW
  Field Advisor
  Coordinated Care and Integrated Case Management Initiative

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Erica Abel, PhD
  Psychologist and Associate Investigator, Pain Research, Informatics, Multi-morbidities, and Education (PRIME) Center, VA Connecticut Healthcare System
  Assistant Clinical Professor, Yale School of Medicine
- Kristina Cordasco, MD, MPH, MSHS
  Core Investigator, Center for the Study of Healthcare Innovation, Implementation and Policy (CSHIP), VA Greater Los Angeles Healthcare System
  Associate Clinical Professor of Medicine, University of California, Los Angeles
- Denise Hynes, BSN, MPH, PhD, RN
  Research Health Scientist, Investigator, Center to Improve Veteran Involvement in Care (CIVIC), VA Portland Health Care System
  Professor, School of Social and Behavioral Health Sciences, College of Public Health and Human Sciences, Oregon State University
- Kristin Mattocks, PhD, MPH
  Associate Chief of Staff/Research & Education, VA Central Western Massachusetts
  Associate Professor, University of Massachusetts Medical School

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.