# SUMMARY AND DISCUSSION

## SUMMARY OF KEY FINDINGS

To inform the VA CC&ICM initiative, we conducted a multi-stage review of evidence for care coordination models. We identified 16 eligible SR addressing care coordination interventions, and further examined 29 relevant primary research studies. We also conducted 11 key informant interviews with those who have implemented care coordination models. Key findings include:

- One SR reported that high-intensity models and/or multidisciplinary plans were required for effectiveness (in combination with selection criteria noted above).
- Most SR reported unclear or inconsistent effects of care coordination models in reducing hospitalizations or ED visits.
- Primary studies reporting effective interventions were conducted in a variety of settings, including rural community hospitals, academic medical centers in urban settings, and public hospitals serving largely poor and uninsured populations.
- Approaches to improve patient-provider communication included coaching patients, role-playing, and attending appointments with patients.
- SR, primary studies, and interviews provided little information on specific tools or approaches used to assess patient trust or working alliance or health care team integration.
- Key informant interviews suggested variation in sustainability of care coordination interventions, with substantial adaptation occurring among many of those that have continued.

Care coordination models were complex and differed along multiple dimensions, thus presenting substantial challenges for SR authors in summarizing and comparing results across studies. Four SR drew conclusions with regard to key intervention characteristics, with 2 highlighting selection criteria, 1 indicating importance of high-intensity model (defined by lower caseload and more patient contacts) and multidisciplinary plans, and 2 finding no key characteristics. Several SR seeking to examine key characteristics and/or organizational settings of care coordination models reported difficulty finding sufficient published evidence to address these questions.

Among 11 primary studies demonstrating effective care coordination models, none reported specific tools or approaches for measuring patient trust or health care team integration. Key informant interviews did not provide additional information on these areas. Interventions used a variety of approaches to improve communication between patients and providers, including coaching and role-playing. In some interventions, care coordinators also directly communicated with providers on patients’ behalf, including participation at outpatient appointments.

Some interviewees described adaptation of the intervention over time to address evolving priorities for health care organizations. Some also highlighted the difficulty of modifying health and social factors contributing to need for acute care utilization among many patients in the highest risk category. There were suggestions that there may be more benefit in focusing on patients at somewhat lower risk and improving health care processes for larger groups of patients.

## IMPLICATIONS FOR POLICY

It remains unclear whether care coordination interventions should be implemented in particular health care settings and how they may be adapted to improve effectiveness and sustainability. Two SR highlighted the importance of carefully selecting patients for care coordination interventions. The VA CC&ICM initiative has implemented several tools for evaluating Veteran needs and matching the level of care coordination services to those needs. The CC&ICM team has conducted site visits to assess the use of these tools and implementation of care coordination models at pilot VA facilities. It will be important for VA to evaluate the feasibility of applying these tools more widely, and the effects of implementing such tools on delivery of services and patient outcomes. Additionally, because VA medical centers and clinics are located in a variety of settings, it will be important to understand differences in utility of these tools across large and small sites, and those serving urban and more rural communities.

VA facilities differ in the number and types of care coordination services and programs that are offered. Understanding what is available at a particular facility may be challenging for Veterans, their caregivers, and VA clinical staff. A key goal of the CC&ICM initiative is to standardize care coordination across VA sites, and this may improve access and use of appropriate services for Veterans. However, the CC&ICM initiative also acknowledges the importance of flexibility to adapt care coordination models to accommodate local circumstances. Our interview results also support the importance of local adaptations for uptake and sustainability of care coordination interventions. A potential avenue to achieving more consistency of services while allowing flexibility may be to align services and programs based on program goals and Veteran needs; this information could then be collected in a central hub that Veterans and/or VA staff can use to find appropriate services. It may be also be valuable to provide educational materials as part of the CC&ICM initiative to guide adaptations (eg, highlighting the key program goals or outcomes, and distinguishing between core components and more flexible options). Additionally, evaluation of implementation should consider which adaptations were made and the rationale to support these.

One SR indicated that a high-intensity (defined using case load and patient contacts) or multidisciplinary care coordination model was more likely to be successful. Our examination of effective primary research studies also found a high number and frequency of patient contacts, often involving home visits. Therefore, it may also be valuable to understand which VA programs or models are most similar to these high-intensity interventions, and consider whether it would be cost-effective to implement more broadly. Currently, such high-intensity care coordination programs serve a limited number of Veterans with specific diagnoses (eg, VA Mental Health Intensive Case Management for those with bipolar disorder or schizophrenia).^60^

Finally, there may be specific patient groups that would benefit more from models that go beyond additional care coordination services (eg, by a nurse and/or social worker). For example, VA Primary Care Mental Health Integration (PCMHI)^61^ is a collocated, collaborative model where mental health staff have frequent structured and informal communications with primary care staff. The national implementation of VA PCMHI sought to improve access to mental health services for Veterans and improve integration of mental health concerns with other aspects of care. The VA has also been interested in potentially implementing different models of integrating oncology and palliative care for cancer patients.^62^

## EVIDENCE GAPS AND FUTURE RESEARCH NEEDS

Our examination of primary research studies suggested that those with observational quasi-experimental designs were more likely to report reductions in hospitalizations and/or ED visits. Observational studies may have residual confounding and are more likely to be affected by publication bias, as there are no requirements for a priori registration (with explicit description of primary outcomes and analysis strategy).

Studies of effective care coordination models did not report standardized tools used to assess patient trust or care team integration. It may be that these interventions relied on informal assessment by study staff or that there was an assumption that these domains would all improve. However, descriptions of these tools and strategies for assessment will support health systems in evaluating their existing services and implementing new care coordination models.

Finally, multiple SR raised concerns about lack of information on intervention implementation, including fidelity and frequency of various components. To improve evaluation and interpretation of the effectiveness of care coordination interventions, future studies should consider application of frameworks and designs with explicit consideration of implementation outcomes (eg, hybrid effectiveness-implementation designs, Consolidated Framework for Implementation Research[CFIR], and Reach, Effectiveness, Adoption, Implementation, and Maintenance [RE-AIM]).^63–66^ Studies using such frameworks should clearly define the “core” set of key components and describe the “adaptable periphery” of elements that can be adjusted to accommodate the local context.

Therefore, we recommend the following for future research:

- Evaluate future care coordination interventions using randomized designs.
- Consider application of standardized tools to assess patient trust or working alliance, health care team integration, and communication between patients and providers.
- Consider study designs that explicitly consider implementation outcomes in future studies of care coordination models.
- Define “core” intervention components and describe local adaptations, particularly in multi-site studies.

## LIMITATIONS

To address the priorities of our VA partners, this work focused on care coordination models that were effective in reducing hospitalizations and/or ED visits; SR and studies that did not address these outcomes were excluded. While we acknowledge the importance of patient experience outcomes, our discussions with stakeholders and key informant interviews all supported the high priority of acute care utilization for health care system leadership, particularly with regard to sustainability of interventions. We prioritized high- and medium-quality reviews for abstracting detailed results addressing KQ. However, we identified relevant primary studies from all eligible SR. We relied on SR authors’ determination of overall effectiveness and strength of evidence for care coordination models. Because interventions in countries other than the US may be less relevant for the VA, we limited primary studies to those conducted in the US. It is possible that studies conducted in other countries may have been informative for VA policy, despite very substantial differences in health care financing and delivery. We were able to complete interviews with less than half of those whom we invited to participate; it is possible that there was unpublished information on tools and approaches that we were unable to identify.

## CONCLUSIONS

Existing evidence on care coordination models indicate that they have inconsistent effects on reducing hospitalizations and/or ED visits for high-risk community-dwelling adults. It remains unclear whether such interventions should be implemented and how they may be adapted to different health care settings. Implementation of new care coordination services should be carefully evaluated, preferably using randomized designs. Policymakers should also consider whether for certain patient populations, a larger-scale redesign of care models may be necessary to improve continuity and collaboration.