# RESULTS

## OVERVIEW OF ELIGIBLE SYSTEMATIC REVIEWS

Of 2324 unique citations, 72 underwent full-text review (Figure 1). We identified 16 eligible SR, 14 of which examined case management or transitional care interventions,^15–28^ and 2 of which evaluated intensive primary care models (eg, home-based primary care).^29,30^ All SR included a wide range of interventions, using broad definitions for case coordination or intensive primary care models. Four SR included only RCT,^15,21,22,27^ while the others allowed both RCT and observational studies. Three SR included only US studies,^16,20,24^ and the remaining SR included studies conducted in several different countries. Seven SR focused specifically on patients at higher risk for acute care utilization (ie, high-utilizers),^15,18–20,23,24,26^ and 1 SR examined interventions for individuals with frailty.^27^ Six SR were high quality,^19,22,23,25,26,30^ 6 were medium quality,^15,18,20,21,27,29^ and 4 were low quality.^16,17,24,28^ We focused on the 12 medium- and high-quality SR for detailed results addressing KQ. Key characteristics and summary of results from high- and medium-quality SR are shown in Table 2. We also provide descriptions of results for KQ1 and 2 in the following text and in Appendix 7 (along with detailed SR characteristics). SR reported very limited information regarding KQ 3 and 4.

Figure 1 Search & Selection of Eligible Systematic Reviews

## KQ1 WHAT ARE THE KEY CHARACTERISTICS OF CARE COORDINATION MODELS?

All SR provided general descriptions of different components included by interventions, with many providing some information on team composition and frequency of use of certain components (eg, multidisciplinary care plan). Outside of in-person contacts (whether in a clinical setting or at home), the other main form of communication with patients was via telephone. Four SR^19,25,27,30^ specifically addressed whether there are key characteristics for care coordination interventions (Table 2). Hudon et al^19^ used qualitative comparative analysis to examine intervention characteristics of effective case management models, reporting “case-finding…and complexity of health care needs are necessary to produce a positive outcome.” Additionally, selection of cases needed to be combined with either a high-intensity model (defined by authors using caseload and frequency and types of contact with patients) or a multidisciplinary care plan. Smith et al^25^ reported that interventions “targeted at specific risk factor management or focused areas…are more likely to be effective… [while] interventions that have a broader focus…seem less effective.” Van der Elst et al^27^ conducted subgroup analyses by intervention duration and different approaches to address frailty, finding no significant differences. Totten et al^30^ examined home-based primary care and stated “there is not an apparent pattern or cluster of services associated with differences in outcomes.” Additionally, 2 SR^15,29^ sought to determine the key components for care coordination models but were unable to draw conclusions; authors reported challenges due to lack of published information on components and fidelity of intervention implementation.

## KQ2 WHAT IS THE EFFECT OF IMPLEMENTING CARE COORDINATION MODELS?

Of 10 SR examining case or care management and/or transitional care interventions, 2 conducted quantitative meta-analyses,^22,27^ while the remaining SR used qualitative syntheses to describe results^15,18–21,23,25,26^ (Table 2). Six SR evaluated effects on hospitalization, with 5 reporting mixed or unclear results^15,19,21,22,25^ and 1 finding lack of effectiveness.^27^ Among these, Le Berre et al^22^ pooled results for transitional care interventions (most involved nurses who called patients and/or made home visits) for diverse patient populations. Pooled results from 11-35 RCT found no effect at 1 month (risk difference [RD] −0.03, 95% CI −0.05, 0) and some effects at 3-18 months (RD range −0.05 to −0.11). Van der Elst et al^27^ conducted meta-analyses to evaluate effects on hospitalization but examined a diverse set of case management interventions for frail community-dwelling older adults; pooled results from 5 RCT showed that case management did not reduce hospitalizations (odds ratio [OR] 1.13, 95% confidence interval [CI] 0.95, 1.35).

Seven SR examined effects of case or care management and/or transitional care interventions on ED visits (Table 2). Two SR^21,23^ indicated that care coordination interventions reduced ED visits, and both provided descriptive information about included studies. One SR stated that 6 included studies reported reductions in ED visits,^21^ and the other found that the median rate ratio (of care coordination vs control) was 0.63, with interquartile range of 0.41-0.71.^23^ All 5 remaining SR^18–20,22,26^ reported unclear or mixed effects on ED visits, including 1 that conducted pooled meta-analyses over various timeframes (1-12 months).^22^

Only 1 SR on case management evaluated effects on patient experience and, using qualitative synthesis, found inconsistent results.^19^

Two SR evaluated intensive primary care interventions, with the 1 focused on home-based primary care reporting reduced hospitalizations,^30^ and the other describing inconsistent results across studies^29^; both used qualitative syntheses (Table 2). The SR on home-based primary care also found that there was improved patient and caregiver satisfaction (low strength of evidence).^30^

## KQ3 WHAT ARE THE CHARACTERISTICS OF SETTINGS IN WHICH EFFECTIVE MODELS HAVE BEEN IMPLEMENTED?

Only 2 SR addressed characteristics of settings for interventions. 1 SR on case management stated that all but 1 of 16 included studies were single-site, usually in an urban setting.^26^ The other SR sought to address organizational settings for home-based primary care models but was unable to find published information.^30^

To further address KQ 3 (and KQ 4), we identified 272 unique primary studies included by eligible SR, and found 18 RCT^31–48^ and 9 observational studies^49–57^ that were relevant. While 78% of relevant observational studies (n=7)^49–53,55,56^ reported reductions in hospitalizations and/or ED visits, only 22% of RCT (n=4)^34,39,42,44^ demonstrated effectiveness. Additionally, we searched for RCT that were published after the most recent eligible SR. This search resulted in 1048 unique citations, of which 21 underwent full-text review. We identified 2 relevant RCT^47,48^ but both studies reported that interventions were not effective for reducing hospitalizations and/or ED visits.

Characteristics of effective care coordination models described in these studies, their effects and the settings in which they were implemented are summarized in Table 3. We categorized the effective interventions into transitional care, outpatient care or case management (led by nurse or social worker), or other intensive primary care models. These interventions were implemented in a variety of settings, including rural community hospitals and health systems, academic medical centers (in urban settings), and public hospitals serving largely poor and uninsured populations. There was no clear connection between differences in settings, types of intervention and various patient populations.

## KQ4 WHAT ARE THE TOOLS AND APPROACHES USED BY EFFECTIVE MODELS?

No SR commented on tools and approaches used to measure patient trust or care team integration, or to improve communication between patients and providers. Primary research studies described several approaches to improve patient-provider communications, such as coaching patients on how to ask questions, making lists of key concerns, and role-playing visits with providers.^34,42,51,55,58^ In 2 studies, care coordinators supported communication by attending outpatient visits with patients and their providers.^42,55^ No primary research study described specific tools or measures to assess patient working alliance with care coordination staff, care team integration, or patient-provider communications. For 1 intervention, qualitative methods were used to evaluate patient experiences and relationship with care coordinators.^34,59^

## KEY INFORMANT INTERVIEWS

We conducted 11 interviews with investigators and other team members who implemented care models described by relevant primary research studies. Several interviewees described using approaches akin to health coaching (although not called that in the published studies) to improve patient communications with providers. None of the interviews provided additional information on specific tools or approaches used to assess patient working alliance with care coordination staff, care team integration, or patient-provider communications. Review of additional intervention materials provided by some interviewees indicated that assessments of patient experience sometimes included factors conceptually related to patient trust (eg, perception that care coordinator was knowledgeable and understood patients’ needs).

Regarding the sustainability of care coordination interventions, we found great variation in long-term effects. In some cases, interventions were not continued after completion of the research studies. Lack of financial viability was often a key factor in discontinuation of these interventions. Others were substantially modified and adapted to meet changing health system priorities (eg, in targeted patient populations). There was variable success in engaging stakeholders such as hospital leadership and front-line providers. Health care utilization and costs were priorities for those in leadership, and improved patient experiences were not usually sufficient for continuing interventions. One interviewee indicated “a tension between reducing costs/hospitalizations and adding value to the patient.”

In terms of key issues to for future care coordination interventions, some key informants questioned whether acute care utilization by high-risk populations was truly preventable, as these patients often had multiple challenges and health needs that required hospitalization. For example, 1 interviewee stated, “Everything that could be possibly going wrong is going wrong…A lot of these people are going to get readmitted no matter what you do.” There was also concern with current readmission metrics and the ability to make substantial changes within a short timeframe: “30 days doesn’t give you sufficient time…especially in elderly patients with many issues.” Some also suggested that care coordination interventions may work better in those with less severe conditions and/or modifiable factors; an important challenge with such an approach is that the intervention may need to serve a large number of patients before there are appreciable differences in acute care utilization. One individual described it thus: “You can allocate a lot of resources to extremely high need patients…or you can allocate resources to a larger population and … have a smaller impact on individual level, but on population level have greater impact…”

Table 2 Summary of Results for Key Questions 1 and 2 from High- and Medium-Quality Systematic Reviews

Author, Year (Quality, Year of Search) | Included Populations; Study Designs; # Relevant Primary Studies | Synthesis Method | KQ1—What are the key characteristics of care coordination models? | KQ2—What is the effect of implementing care coordination models?
Author, Year (Quality, Year of Search) | Included Populations; Study Designs; # Relevant Primary Studies | Synthesis Method | KQ1—What are the key characteristics of care coordination models? | ↓ Hospitalization? (Y/N) | ↓ ED Visits? (Y/N) | ↑ Patient Experience? (Y/N)
Case Management and Transitional Care Interventions
Di Mauro, 2019^18^ (Medium, 2018) | High-utilizers; RCT, cohort; 3 | Qualitative synthesis | NR | NR | Unclear (inconsistent across studies) | NR
Hudon, 2019^19^ (High, 2017) | High-utilizers with chronic conditions; RCT, cohort, cross-sectional; 4 | Qualitative comparative analysis | Necessary characteristics: “case-finding” (high utilization and/or complexity of needs); AND; High-intensity or multidisciplinary care plan | Unclear (inconsistent across studies) | Unclear (inconsistent across studies) | Unclear (inconsistent across studies)
Iovan, 2019^20^ (Medium, 2017) | High-utilizers; RCT, cohort; 6 | Qualitative synthesis | NR | NR | Unclear (inconsistent across studies) | NR
Van der Elst, 2018^27^ (Medium, 2016) | Frail older adults; RCT; 0 | Quantitative meta-analysis | No significant results in subgroup analyses by: intervention duration; recruitment method; “multi- versus unidimensional approach to frailty” | N | NR | NR
Joo, 2017^21^ (Medium, 2016) | Chronic conditions; RCT; 1 | Qualitative synthesis | NR | Unclear (inconsistent across studies) | Y | NR
Baker, 2018^15^ (Medium, 2015) | Multimorbidity, high-utilizers; RCT; 4 | Qualitative synthesis | “[C]ommon methodologic issues limited our ability to draw conclusions regarding the effectiveness of specific intervention components…” | Unclear (inconsistent across studies) | NR | NR
Le Berre, 2017^22^ (High, 2015) | Older adults with chronic conditions; RCT; 3 | Quantitative meta-analysis | NR | Unclear (inconsistent across studies) | Unclear (inconsistent across studies) | NR
Soril, 2015^26^ (High, 2015) | High-utilizer; RCT, cohort; 3 | Qualitative synthesis | NR | NR | Unclear (inconsistent across studies) | NR
Moe, 2017^23^ (High, 2014) | High-utilizer; RCT, cohort; 3 | Median, IQR for RR | NR | NR | Y | NR
Smith, 2016^25^ (High, 2011) | Multimorbidity; RCT, cohort; 2 | Qualitative synthesis | “[I]nterventions that are targeted at specific risk factor management or focused areas where patients have difficulties, such as with functional ability or medicines management, are more likely to be effective… [while] interventions that have a broader focus…seem less effective.” | N | NR | NR
Intensive Primary Care Interventions
Totten, 2016^30^ (High, 2015) | Chronic conditions and/or disabilities; RCT, cohort; 1 | Qualitative synthesis | “There is wide variation in the services provided as part of [home-based primary care]. [T]here is not an apparent pattern or cluster of services associated with differences in outcomes…” | Y | Y | Y
Edwards, 2017^29^ (Medium, 2017) | High risk for hospitalization or death; RCT, cohort; 7 | Qualitative synthesis | “We had hoped to identify key program features… that may have contributed to the success or failure of these programs. Unfortunately, reporting of key intervention characteristics was inconsistent…” | Unclear (inconsistent across studies) | N | NR

CI=confidence interval; ED=emergency department; IQR=interquartile range; NR=not reported; OR=odds ratio; RCT=randomized controlled trials; RD=risk difference; RR=risk (or rate) ratio

Table 3 Primary Studies—Characteristics and Results of Effective Care Coordination Models

Author, Year; Study Design^*^; N | Intervention Name; Eligibility Criteria | Description of Patient Contacts | Effects of care coordination interventions | | KQ3—Characteristics of settings in which effective models have been implemented?
Author, Year; Study Design^*^; N | Intervention Name; Eligibility Criteria | Description of Patient Contacts | Hospitalizations | ED Visits | KQ3—Characteristics of settings in which effective models have been implemented?
Transitional Care Interventions
Capp, 2017^49^; Cohort; I=406 C=3396 | Bridges to Care; adults with ≥ 2 ED visits and/or hospitalizations in past 180 days | First home visit by community health worker within 24-72 hours, second visit by PCP within 1 week of ED or hospital discharge; 8 visits over 60 days (community health worker, nurse, primary care provider, and/or behavioral health provider) depending on patient needs. | Average # admissions per person, 180 days before enrollment: I=1.04, C=1.15; 180 days after 60-day intervention: I=0.75, C=1.02; Difference of differences= −0.16, P<0.1 | Average # visits per person, 180 days before enrollment: I=5.12, C=4.93; 180 days after 60-day intervention: I=2.79, C=3.60,; Difference of differences=−1.01, P=<0.01 | Large urban academic medical center, Colorado
Hamar, 2016^52^; Cohort; I=560 C=3340 | Care Transition Solution; adults admitted with ≥ 1 condition (COPD, heart failure, myocardial infarction, pneumonia) | Initial visit in hospital with nurse before discharge, then 4 calls over 4 weeks | Proportion with ≥ 1 readmission at 30 days: AOR=0.56 (0.41-0.77); At 6 months: AOR=0.47 (0.35-0.65) | NR | 14 community hospitals in north Texas
Gardner, 2014^51^; Cohort; I=21 C=21 | Care Transitions Intervention; adults participating in Medicare fee-for-service, admitted to hospital | Initial visit in hospital by nurse, home visit “shortly after discharge,” 2-3 phone calls during 30-day post-discharge period | Propensity score matched # readmissions at 6 months: I=0.65, C=0.93 P=0.01 | Propensity score matched # visits at 6 months: I=0.44, C=0.50 P=0.55 | 6 community hospitals, Rhode Island
Coleman, 2006^34^; RCT; I=379 C=371 | Care Transitions Intervention; older adults (≥65) admitted with ≥ 1 condition (stroke, heart failure, diabetes mellitus, etc) | Nurse met patients in hospital before discharge, home visit within 48-72 hours of discharge, then 3 more times during 28-day post-discharge period. | Proportion with ≥ 1 readmission at 30 days: I=0.08, C=0.12 AOR=0.59 (0.35, 1.00), P=0.048; At 90 days: I=0.17, C=0.23 AOR=0.64 (0.42, 0.99), P=0.04; At 180 days: I=0.26, C=0.31 AOR=0.80 (0.54, 1.19), P=0.28 | NR | Community health system, Colorado
Naylor, 1999^39^; RCT; I=177 C=186 | Transitional Care Model; older adults (≥65) admitted with ≥ 1 condition (heart failure, respiratory infection, orthopedic procedure, etc.) | Initial nurse visit within 48 hours of admission, visits at least every 48 hours during admission, home visits after discharge (first within 48 hours, second 7-10 days post-discharge, additional visits based on patients’ needs), weekly nurse-initiated phone contact | Proportion with ≥ 1 readmission at 24 weeks: I=0.20, C=0.37 P=<0.01 | NR | 2 urban hospitals affiliated with University of Pennsylvania
Outpatient Care or Case Management
Shah, 2011^55^; Cohort; I=98 C=160 | Care Management Program; adults aged 18-64, <200% federal poverty level, uninsured, “met frequent user criteria” | Care managers (social worker or medical office assistant) met with patients at least monthly in the home and/or clinic, for variable lengths of time (care manager decided when patient graduated program) | Adjusted ratio of # of admissions per year (I:C) was 0.81, P=0.38 | Adjusted ratio of # of visits per year (I:C) was 0.67, P<0.001 | Public safety-net hospital and clinics in Kern County, California
Peikes, 2009^42^; RCT; Mercy Medical Center (1 of 15 sites)—I=669, C=467 | Medicare Coordinated Care Demonstration; adults participating in Medicare fee-for-service and with ≥ 1 condition (heart failure, COPD, etc.) | Nurse completed in-person evaluation within 2 weeks of enrollment, contacted patient at least monthly, 69% were in-person (either at home or during clinic visit) | Average # admissions per person per year: I= 1.15, C=0.98 P=0.02 | NR | Mercy Medical Center—rural community hospital, Iowa
Shumway, 2008^19^; RCT; I=167, C=85 | Comprehensive case management; adults with ≥ 5 ED visits in past 12 months and had “psychosocial problems that could be addressed with case management” | Social workers completed assessments, individual and group supportive therapy, assistance to a variety of community resources, and “assertive community outreach” (frequency and schedule of patient contacts NR) | Effect size NR, P=0.08 for treatment effect in adjusted model for visits over 2 years | Effect size NR, P<0.01 for treatment effect in adjusted model for visits over 2 years | Urban public hospital in San Francisco, California
Sommers, 2000^56^; Cohort I=280 C=263 | Senior Care Connections; adults ≥65 with difficulty in ≥1 instrumental activity of daily living and 2 ≥ chronic conditions | Initial home visit with case manager (nurse or social worker), treatment plan drafted by care team (nurse, social worker, primary care provider), patients contacts via phone, home visits, small group sessions, or office/hospital visits at least once every 6 weeks | # of admissions per person per year at baseline: I=0.35, C=0.06; during year 1: I=0.38, C= 0.34; during year 2: I=0.36, C=0.52; P=0.03 | Proportion with ≥1 visit at baseline: I=0.09, C=0.06; during year 1: I=0.20, C=0.17; during year 2: I=0.21, C=0.17; P=0.77 | Primary care clinics in San Francisco Bay area, California
Other Intensive Primary Care Models
Crane, 2012^50^; Cohort; I=34 C=36 | Drop-in group medical appointments; uninsured, family income ≥ 200% federal poverty level, ≥ 6 ED visits in past year | Twice-weekly groups sessions, short individual visit right after; direct phone access to nurse care manager; team included nurse, primary care and behavioral health providers | NR | Median # visits per month during 1 year before: I=0.58, C=0.58; during 1 year after: I=0.23, C=0.42; Difference in differences: 0.23, P=0.005 | Rural community hospital, North Carolina
Meret-Hanke, 2011^53^; Cohort; I=3889 C=3103 | Program for All-Inclusive Care for the Elderly; adults >65, with functional limitations or dementia, income <300% Supplemental Security Income | Interdisciplinary care teams provided care management, clinical monitoring, and updated care plan in response to changes in enrollee’s health and functional status | Propensity score matched any hospitalization at 6 months: AOR 0.35, P“0.01; At 2 years: AOR 0.16, P<0.01 | NR | National US program

AOR=adjusted odds ratio; C=control group; COPD=chronic obstructive pulmonary disease; ED=emergency department; I=intervention group; RCT=randomized controlled trial

* Study designs were either RCT or observational cohorts with comparative controls