# METHODS

## TOPIC DEVELOPMENT

### Conceptual Framework of Care Coordination Models

To guide scope refinement and protocol development, we reviewed several existing resources on integrated care or care coordination, including the Agency for Healthcare Research and Quality (AHRQ) Care Coordination Atlas^5^ and a previous ESP report on care coordination frameworks.^7^ We examined specific frameworks, such as Care Coordination in Chronic and Complex Disease Management,^8^ the Integrated Team Effectiveness Model,^10^ Rainbow Model for Integrated Care,^11^ and Coordination Networks.^12^ In collaboration with VA stakeholders from the Office of Care Management and Social Work Services and the Office of Nursing Services, and our technical expert panel, we selected the framework for Care Coordination in Chronic and Complex Disease Management as the most applicable to the goals of this current review (Table 1). This framework focuses on characteristics, processes, and interactions within and between health care teams. We considered that evidence addressing these areas would be most relevant to support the goals of the VA CC&ICM initiative. We further adapted this framework in 2 areas: 1) specification that team roles include who contacted patients (and in what manner); and 2) reorganization of outcomes by patients (eg, patient experience, quality of life, and survival), health care teams (eg, work satisfaction and burnout), and health systems (eg, acute care utilization and costs). While health care utilization and costs may be measured at the patient level (eg, number of admissions or ED visits per person), we considered such outcomes to be oriented towards the priorities of the health care system (and payers).

Applying this framework and in accordance with the priorities of our VA partners, we defined effective care coordination interventions as those that reduced hospitalizations and/or ED visits. We sought information about the key characteristics of effective interventions, particularly with regard to elements depicted in the columns on Context & Setting and Coordinating Mechanisms (Table 1). For example, key characteristics may include multidisciplinary teams (vs primarily single case manager), and home visits (vs telephone contacts and/or outpatient visits). To support ongoing implementation and evaluation of care coordination programs in the VA, we also searched for evidence on tools and approaches that were used to assess Emergent Integrating Conditions (eg, trust within teams) and Coordinating Actions (eg, within team communication); such tools may assist programs in monitoring implementation progress before final outcomes are available. To these elements from the Care Coordination Framework, we additionally considered tools to assist with evaluating patient trust or working alliance with the care coordination team, and those to improve communication between patients and providers. Finally, to support interpretation of the evidence with regard to applicability to VA health care settings, we sought information on the characteristics of health care systems and communities where effective interventions have been implemented.

Table 1 Adapted Framework for Care Coordination in Chronic and Complex Disease Management^*^

| Context & Setting | Coordination Mechanisms | Emergent Integrating Conditions | Coordinating Actions | Outcomes
Within Teams | - Team composition; - Experience & history; - Power distribution; - Resources | - Plans, rules, & tools; - Objects, representations, artifacts, & information systems; - Roles (eg, who contacts patients & how); - Routines; - Proximity | - Accountability; - Predictability; - Common understanding; - Trust | - Situation monitoring; - Communication; - Back-up behavior | - [underlined: Patients]; - (eg, patient experience, quality of life, survival); - [underlined: Health care teams] (eg, job satisfaction); - [underlined: Health systems] (eg, acute care utilization, costs)
Between Teams | - Multiteam system composition; - Linkages between teams; - Alignment of organizational cultures/climates; - Governance & payment structure | | | - Boundary spanning; - Information exchange; - Collective problem-solving & decision-making; - Negotiation; - Mutual adjustment

* Original framework by Weaver et al (2018)^8^

### Key Questions (KQ)

For community-dwelling adults with a variety of ambulatory care sensitive conditions and/or at higher risk of having repeat hospitalization or ED visits:

KQ1 What are the key characteristics of care coordination models (of varying types) that aim to reduce hospitalization or ED visits?
KQ2 What is the effect of implementing these care coordination models on hospitalizations, ED visits, and patient experience (eg, Consumer Assessment of Healthcare Providers and Systems)?
KQ3 What are the characteristics of settings in which effective models have been implemented?
KQ4 Among effective models, which approaches/tools have been used to:
  a) Measure patient trust or working alliance?
  b) Measure team integration?
  c) Improve communication between patients and providers?

To address these KQ, we first focused on identifying eligible SR on care coordination models. We determined that a review of reviews would be appropriate given the broad scope and anticipated heterogeneity in types of care coordination models, as well as patient populations. In order to address likely gaps in SR results, particularly with regard to KQ 3 and 4, we also examined primary research studies of effective interventions and conducted key informant interviews with those who implemented and evaluated interventions.

## SEARCH STRATEGY

We searched for English-language SR in the following databases, from inception until September 2019: MEDLINE, CINAHL, Embase, Cochrane Database of Systematic Reviews, AHRQ Evidence-based Practice Center reports, and VA ESP reports. The search terms included MeSH and free text for care coordination interventions (eg, care or case management, interdisciplinary care, and intensive primary care), and systematic reviews (Appendix 1). We anticipated that eligible SR may not provide sufficient information, particularly with regard to KQ3 and 4. Therefore, we supplemented results from eligible SR with: 1) examination of primary research studies included by SR; 2) search of MEDLINE and Embase from the year of the most recent eligible SR (2018) until February 2020 for relevant randomized controlled trials (RCT) on care coordination models (Appendix 2); and 3) interviews with investigators and/or teams who implemented interventions described in research studies thus identified (see below).

## STUDY SELECTION

Duplicates were removed from SR search results and uploaded into DistillerSR (Evidence Partners, Ottawa, Canada). Using prespecified inclusion and exclusion criteria (Appendix 3), titles and abstracts were screened for eligibility. Eligible populations of interest included community-dwelling adults with a range of ambulatory care sensitive conditions (eg, heart failure and chronic lung disease) and/or at higher risk for acute care episodes. If a review focused exclusively on interventions for a single health condition, it was excluded. Eligible interventions covered different care coordination models, such as care or case management and home-based primary care (Appendix 3). We required that eligible reviews reported inclusion of hospitalizations and/or ED visits as outcomes of interest in objectives or results. Articles underwent full-text review if at least 1 reviewer deemed it eligible during abstract screening. Exclusion of articles at screening required agreement of 2 reviewers. At full-text review, 2 individuals separately determined inclusion/exclusion and then resolved any conflicts through discussion. When consensus could not be reached, disagreements were discussed with a third reviewer.

From each eligible SR, we identified all included primary studies and 2 reviewers evaluated them for potential relevance to KQ3 and 4. In addition to the above criteria for SR, we applied the following: conducted in US, and RCT or quasi-experimental observational studies (eg, comparative control cohort or interrupted time series).^13^ To supplement this group of relevant primary studies, we also screened search results for RCT of care coordination models from 2018 until February 2020. Two reviewers applied the same criteria used to evaluate SR, along with the additional requirement for RCT conducted in US.

## QUALITY RATING & DATA ABSTRACTION

We assessed the quality of eligible SR using criteria adapted from AMSTAR 2,^14^ and rated overall quality as high, medium, or low (Appendix 4). In general, a high-quality SR met all applicable criteria (ie, at least “partial Yes” for all questions). Two reviewers independently rated each SR, and consensus was reached through discussion.

We abstracted data from all eligible SR on: target population(s); dates of search queries; and number and characteristic of included primary studies (location, setting, and study design). Additionally, from medium- and high-quality SR, we abstracted detailed results on: description of care coordination model characteristics; pooled effects (or qualitative summaries) for hospitalizations, ED visits, and/or patient experience; characteristics of settings; and tools and approaches used to measure patient trust or working alliance, assess health care team integration, and/or improve communication between patients and providers.

From relevant primary studies on care coordination models, we abstracted data on effectiveness for main outcomes; participant, intervention and setting characteristics; and tools and approaches. Because the primary studies frequently referenced other studies for information on intervention characteristics, we also reviewed these associated studies for data relevant to KQ3 and 4.

For both SR and primary studies, data abstraction was done by 1 reviewer and results overread by a second reviewer.

## DATA SYNTHESIS FOR SYSTEMATIC REVIEWS & RELEVANT PRIMARY STUDIES

We focused on results from SR to evaluate KQ 1 and 2, because this allowed us to address a broad scope including many types of care coordination interventions across diverse high-risk populations. Given this heterogeneity, we undertook a qualitative synthesis of these results. We summarized SR results on key characteristics of care coordination models, and effectiveness for hospitalizations, ED visits, and/or patient experience. We also included strength of evidence determinations by SR, if these were stated. Few SR provided information on KQ 3 and 4; we highlighted these results when provided.

For identified relevant primary studies, we focused on those reporting successful reductions in hospitalizations and ED visits, and summarized information from these studies that were relevant for KQ3 and 4. To address remaining gaps, we also included information from associated articles (eg, methods papers) and websites referenced by primary studies.

## INTERVIEWS WITH KEY INFORMANTS WHO IMPLEMENTED CARE COORDINATION MODELS

We conducted semi-structured interviews with research investigators and members of teams who implemented care coordination models, as described in relevant primary studies (identified from both eligible SR and updated search for RCT). We included individuals from relevant primary studies, regardless of effectiveness in reducing hospitalizations and/or ED visits. We initially invited 22 individuals by email, and contacted another 3 individuals per recommendations of respondents. We completed interviews with 11 participants.

The main focus of these interviews was to address gaps in the published literature regarding tools and approaches. We also addressed intervention uptake and sustainability, as this information may be particularly useful to our VA stakeholders. Interview guides included questions in each of these areas and were individually adapted using published or online information about the interventions. A general version of the interview guide is provided in Appendix 5. Interviews lasted about 30 minutes and were audio-recorded. We reviewed contemporaneous notes and audio-recordings to first develop summaries for each care coordination intervention. We then examined summaries for all interviews to provide overall themes.

## PEER REVIEW

A draft version of this report was reviewed by 6 technical experts, as well as VA operational partners. Their comments and our responses are presented in Appendix 6.