# INTRODUCTION

Complexity of health care services and care fragmentation contribute to adverse health outcomes and poor patient experiences of care.^1–4^ Over the past 20 years, there has been substantial interest and investment in developing and implementing care coordination interventions, particularly for patients who have demonstrated high utilization of acute care services.^5,6^ Although there are multiple definitions for care coordination models, such interventions usually involve systematic strategies that aim to improve continuity and bridge transitions of care.^5,7,8^ Often, this takes the form of care or case management, in which a designated person or team helps patients manage their medical care and navigate interactions with the health care system(s). While there have been a variety of care coordination models evaluated across diverse settings, it remains unclear whether these interventions can sufficiently address gaps in care and improve patient outcomes.

The VA Care Coordination and Integrated Case Management (CC&ICM) initiative was launched in 2016, as a collaboration between the VA Offices of Care Management and Social Work, and Nursing Services.^9^ The main goals of this initiative are to standardize and integrate care coordination services across all VA facilities and points of care for Veterans. The CC&ICM initiative has developed several tools for identifying Veterans who may benefit from various levels of care coordination services; it is currently focused on evaluation of care coordination at pilot VA sites and implementation of additional tools to assist with team integration and communication with patients. To assist the CC&ICM initiative, the VA ESP was asked to review evidence on implementation and outcomes of various care coordination models.

In this report, we summarize results from eligible systematic reviews (SR) on key characteristics and effectiveness of care coordination interventions for diverse adult populations at high risk for adverse outcomes. Additionally, we present results from primary research studies of effective interventions (ie, those able to reduce hospitalizations and/or emergency department [ED] visits) regarding tools and approaches used to assess patient trust and care team integration, and to improve communication between patients and providers. To better understand which results may be most applicable to VA, we also provide information about the settings in which effective care coordination models were implemented. Finally, we present results from key informant interviews to address remaining gaps in the published literature, particularly with regard to tools and approaches used by various interventions.