# APPENDIX 7 DETAILED CHARACTERISTICS AND RESULTS FROM MEDIUM- AND HIGH-QUALITY SYSTEMATIC REVIEWS

Author, Year (Quality, Year of Search); # Relevant Primary Studies | Included Populations; Study Designs | Included Relevant Interventions | Main Objective(s); Results Summary
Case Management and Transitional Care Interventions
Di Mauro, 2019^18^ (Medium, 2018); 3 | “[frequent user] adult patients who visit the ED”; RCT, cohort | “Case Management…is a collaborative approach used to assess, plan, facilitate and coordinate healthcare related matters…It aims at meeting patients’ and their families’ health needs through communication and available resources, thus, improving individual and healthcare system outcomes…” | “to examine if and how the [case management] programs are implemented to reduce the number of [frequent user] visits to the ED.”; “Ten papers showed…decrease in visits to the ED (from 14% to 58.5%) and in… 3 studies the results were insufficient to prove this utility.”
Hudon, 2019^19^ (High, 2017); 4 | “adult frequent users…with physical chronic disease”; RCT, cohort, cross-sectional | “[Case management is] a collaborative approach to ensure, coordinate, and integrate care and services for patients, in which a case manager evaluates, plans, implements, coordinates, and prioritizes services on the basis of patients’ needs in close collaboration with other health care providers…” | “to identify characteristics of [case management] that yield positive outcomes among adult frequent users with chronic disease in primary care.”; “analysis revealed that the case-finding characteristic (ie, high frequency of health care visits) and complexity of health care needs are necessary…; [P]ositive outcomes were associated with the following 2 sufficient characteristics when each was combined with this necessary condition: high-intensity [case management] intervention and presence of a multidisciplinary/interorganizational care plan”
Iovan, 2019^20^ (Medium, 2017); 6 | “population studied…was classified as super-utilizer”; RCT, cohort | Case management:; - “Holistic approach to care considering a patient’s complex medical and social needs…; - Connects patients with existing community resources; - Creates a continuum of care that addresses medical, financial, psychosocial, and behavioral needs…; Care coordination:; “Thoughtful review of a patient’s medical needs, resulting in more effective transitions between providers…” | “systematic review of interventions aimed at reducing prehospital and emergency care use among super-utilizer populations in the United States.”; “17 of 21 case management studies investigated intervention impact on ED use. Of those, 13 showed a reduction in utilization, yet only 5 of these 17 studies (29%) had a control group. Among the 5 studies with a control group, 3 showed some degree of positive impact of the intervention on ED utilization, including 2 of the 3 RCTs…; [M]ethodological and study design weaknesses—especially regression to the mean—were widespread and call into question reported positive findings.”
Van der Elst, 2018^27^ (Medium, 2016); 0 | “60 years or older, diagnosed as frail, and community-dwelling”; RCT | “Case management – a collaborative process of assessment, planning, facilitation, care coordination, evaluation, and advocacy for options and services to meet an individual’s and family’s comprehensive health needs through communication and available resources to promote quality, cost-effective outcomes.” | “What effect do interventions have on frail community-dwelling older adults in terms of mortality, hospitalization… and institutionalization? [H]ow do age, study duration, and the multi- versus unidimensional approaches of frailty and recruitment influence the effect of an intervention?”; “pooled OR for hospitalization when allocated in the experimental group was 1.13 [95% CI: 0.95, 1.35] for case management…; The influence of duration of intervention…multi- versus unidimensional approach to frailty, and recruitment [method] on the effect of an intervention was explored…[in] sub-analyses… but with no significant results.”
Joo, 2017^21^ (Medium, 2016); 1 | “[adult] populations who were diagnosed with chronic illnesses”; RCT | “Case managers, who often work with multidisciplinary teams, are located within the space of transitional care, which means they are able to do continuous follow-up care, timely transitional care and patient-centred care as patients move from hospitals to their communities…” | “synthesizes recent evidence of the effectiveness of case management in reducing hospital use by individuals with chronic illnesses”; “All [10] studies compared hospital readmission…in the intervention and control groups… Three of the studies reported statistically significant reductions in hospital readmissions… Three other studies…reported reduced readmissions but no statistically significant results… The remaining studies… reported no effect on readmission rates.; Six studies reported the number of ED visits as an outcome.; Five studies found a statistically significant reduction in the number of ED visits in pre- and post- [case management] intervention analysis…[T]he sixth study…found reductions…for the [case management] group over the control group, [but] the results were not significant.”
Baker, 2018^15^ (Medium, 2015); 4 | Adults in 1 of 3 categories: “a) 2 or more chronic medical conditions, b) at least 1 chronic medical condition + depression, and c) high past or predicted utilization”; RCT | “patient-focused, comprehensive care management intervention (areas of focus included some combination of self-management, healthcare system navigation, self-efficacy, symptom monitoring, symptom management, etc.) targeting the “whole” patient (e.g. including nurse- or case-manager led interventions, integrated care team strategies, group interventions)” | “What are the necessary components and appropriate intensity of effective care management interventions?”; “Seven studies measured hospital admissions and readmissions in the post-intervention period; however, only 2 of these studies showed an improvement in [hospital readmission]…; [C]ommon methodologic issues limited our ability to draw conclusions regarding the effectiveness of specific intervention components…[I]nsufficient detail on implementation fidelity and participant adherence to the interventions limited any substantive observations on the relationships between intervention content and intensity and any patient benefits.”
Le Berre, 2017^22^ (High, 2015); 3 | “Patients 65 years old or older with at least 1 [chronic disease] who have been hospitalized and are being discharged back to home”; RCT | “[Transitional care] interventions comprising all the following elements: (1) aimed at providing coordination and continuity of care; (2) pre-arranged structured post-discharge follow-up (e.g., home visits, phone calls); (3) at least 1 follow-up starting within 30-days post-discharge.” | “to determine the effectiveness of interventions targeting transitions from hospital to the primary care setting for chronically ill older patients.”; “The risk of readmission in [transitional care] was lower than in [usual care] at 3 months post-discharge (RD: −0.08 [−0.14, −0.03]; NNT: 7), 6 months post-discharge (RD: −0.05 [−0.09, −0.00]; NNT: 20), at 12 months post-discharge (RD: −0.11 [−0.17, −0.05]; NNT: 9), and at 18 months post-discharge (RD: −0.11 [−0.21, −0.01]; NNT: 9). No significant change was observed at 1 month… The risk of an ED visit… was lower… at 3 months post-discharge (RD: −0.08 [−0.15, −0.01]; NNT: 13). No significant change was observed at 1, 6, and 12 months…”
Soril, 2015^26^ (High, 2015); 3 | “general adult frequent ED user”; RCT, cohort | “…case or care management is considered a comprehensive, interdisciplinary approach taken to assess, plan, personalize, and guide an individual’s health services to promote improved patient and health system outcomes.” | “to establish the effectiveness of interventions aimed at reducing the ED utilization, in comparison to usual care, for individuals who are frequent users of the ED”; “Compared to the control groups, 1 RCT reported no change in the mean number of ED visits following [case management], whereas the second RCT reported a minor decrease in median ED visits among those in the intervention group. Of the 10 comparative cohort studies…, 9 studies reported outcomes related to the change in ED visits: 8 studies observed a decrease in the mean (between −0.66 and −37 ED visits) [or median number of ED visits (between 2.28 and −20 ED visits) compared to the controls or before [case management]; and 1 study reported an increase of 2.79 median ED visits post-intervention…”
Moe, 2017^23^ (High, 2014); 3 | “adult frequent ED users”; RCT, cohort | “Case management involved multidisciplinary teams, including physicians, nurses, psychologists, social workers, and/or housing and community resource liaisons, who developed tailored care strategies for patients and linked them to necessary services.” | “to summarize experimental studies evaluating the effectiveness of interventions targeting adult frequent ED users at reducing ED visit frequency and improving hospital admissions…”; “Post- versus pre-intervention rate ratios were calculated for 25 studies and indicated a significant visit decrease in 21 (84%) of these studies. The median rate ratio was 0.63 (interquartile range = 0.41 to 0.71).”
Smith, 2016^25^ (High, 2011); 2 | “people… with multimorbidity”; RCT, cohort | “…organizational changes delivered through practitioners or directly to patients. For example, any changes to care delivery such as case management or the addition of different healthcare workers such as a pharmacist…” | “To determine the effectiveness of health service or patient oriented interventions designed to improve outcomes in patients with multimorbidity in primary care and community settings”; “Five studies reported outcomes on health service utilization…[One] reported significant improvements for intervention group…relating to hospital admissions, whereas [four studies] found no significant difference in outcomes…; The results indicate that it is difficult to improve outcomes in this population but that interventions focusing on particular risk factors or functional difficulties in patients with co-morbid conditions or multimorbidity may be more effective.”
Intensive Primary Care Interventions
Totten, 2016^30^ (High, 2015); 1 | “Adults with chronic illnesses or disabilities”; RCT, cohort | Home-based Primary Care:; “1) Visits by a primary care provider…; 2) Visits to a patients home…; 3) Longitudinal management…; 4) Comprehensive primary care…” | “To assess the available evidence about home-based primary care (HBPC) interventions for adults with serious or disabling chronic conditions.”; “The strongest evidence (moderate) was that HBPC reduces hospitalizations and hospital days. Reductions in emergency and specialty visits and in costs were supported by less strong evidence, while no or unclear effects were identified on hospital readmissions and nursing home days…; HBPC had a positive impact on patient and caregiver experience, including satisfaction, quality of life, and caregiver needs, but the strength of evidence for these outcomes was low…; There is wide variation in the services provided as part of HBPC interventions. In the evidence presently available there is not an apparent pattern or cluster of services associated with differences in outcomes. Most included assessment and coordination…Four studies examined the incremental impact of additional services to HBPC.”
Edwards, 2017^29^ (Medium, 2017); 7 | “Patients identified as high risk for hospital admission and/or death”; RCT, cohort | “We classified programs as primary care replacement (home based), primary care replacement (clinic-based), or primary care augmentation, and assessed the impact of outcomes separately for each category…” | “to classify interdisciplinary, multicomponent [intensive primary care] programs according to program characteristics, and to evaluate the effectiveness of these programs in reducing hospitalizations, emergency department…visits, and mortality among patients at high risk for hospitalization or death.”; “Most studies showed no impact of intensive primary care on mortality or emergency department use, and the effectiveness in reducing hospitalizations varied…The programs varied in the way they identified and screened patients for enrollment, though most focused on older adults with functional limitations… All programs utilized multidisciplinary staff to meet a range of patient needs, and most commonly included physicians, nurses, social workers, physical therapists, mental health providers, and pharmacists… Given the negative results of many of these studies, it is possible that attempts to manage complex care using large multidisciplinary teams may be ineffective for some high-needs patients, as the burden of coordination may outweigh the benefits of the specialized skills of each team member… We had hoped to identify key program features, such as patient selection criteria, that may have contributed to the success or failure of these programs. Unfortunately, reporting of key intervention characteristics was inconsistent… In addition, the data collected on intervention fidelity, implementation process, and contextual factors at individual intervention sites varied among studies.”

CI=confidence interval; ED=emergency department; NNT=number needed to treat; OR=odds ratio; RCT=randomized controlled trials; RD=risk difference