# APPENDIX 5 KEY INFORMANT INTERVIEW GUIDE

A. INTERVENTION INFORMATION GAPS
  1. Thank you. In this first part of the interview we’d like to get your perspective on and experience with [name of intervention], as well as ask some specific questions about your project.
  2. So to start, we have read your article in [journal], but could you please briefly tell us about your experience with this project?
  3. Now I have some specific questions on your study. As a quick reminder, your responses to these might be connected to your study in the report.
    a. If unclear in published studies—Who was the team lead for care coordination? (eg, nurse, social worker, etc.)
    b. Was there collaboration between clinical teams in primary care and specialty care? If so, please describe.
      - Were tools or surveys used to assess team integration?
    c. Were there specific tools or approaches used to improve communication between patients and providers?
      - Were tools or surveys used to assess quality of communication between patients and providers?
    d. Were tools or surveys used to assess patient trust or working alliance?
    e. How were community groups involved?
      - [underlined: PROBE:]
        - Community service groups to assist older adults, community advocacy groups for uninsured
B. UPTAKE AND SUSTAINABILITY
  Now we’d like to ask some questions regarding the uptake and sustainability of your intervention. The responses on these questions will be kept private and reported only in summary (as in major themes).
  1. Aside from team members, who were some of the stakeholders that influenced the planning, uptake and sustainability of your intervention?
    a. What role did these stakeholders play?
    b. How did you engage these stakeholders in discussions to determine which outcomes were important?
      - [underlined: PROBE:]
        - Local leadership, frontline staff, providers, patients, other important groups or individuals?
  2. Is this intervention still in place at your facility/institution?
    If YES
    a What has the long-term impact been?
      - [underlined: PROBE:]
        - Could you elaborate more on the long-term provider and patient satisfaction?
        - Is there ongoing (or future) evaluation planned?
    IF NO
    b Why not?
C. OVERALL EXPERIENCE/REFLECTION ON INTERVENTION
  1. To wrap up, we just have 2 final questions about your overall experience with this intervention.
  2. First, what about your intervention seemed to work well?
  3. Lastly, what about your intervention would you do differently next time?
D. IS THERE ANYTHING ELSE YOU’D LIKE TO ADD THAT I DIDN’T ASK ABOUT?