# APPENDIX 4 QUALITY ASSESSMENT

## 4.1 QUALITY ASSESSMENT CRITERIA FOR SYSTEMATIC REVIEWS (MODIFIED AMSTAR 2)^14^

## 4.2 QUALITY ASSESSMENT FOR ALL ELIGIBLE SYSTEMATIC REVIEWS

Author, Year | Research Questions include components of PICO? | Protocol established prior to conduct of review? | Explained selection of included study designs? | Comprehensive search strategy used? | Dual review for inclusion? Dual review for data extraction? | Assessed quality? | Meta analyses: Appropriate statistical methods and investigation of publication bias? | Reported any potential conflicts of interest? | Overall Quality
Baker, 2018 ^15^ | Yes | Partial Yes | No | Partial Yes | Yes | Yes | NA | Yes | Medium
Bleich, 2015 ^16^ | Yes | Partial Yes | Yes | No | Yes | No | NA | Yes | Low
De Pourcq, 2017 ^17^ | No | No | Yes | Yes | Yes | Partial Yes | NA | Yes | Low
Di Mauro, 2018 ^18^ | Yes | Partial Yes | No | Partial Yes | Yes | Yes | NA | Yes | Medium
Edwards, 2017 ^29^ | Yes | Partial Yes | No | Yes | Yes | Yes | NA | Yes | Medium
Hudon, 2019 ^19^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Iovan, 2019 ^20^ | Yes | Partial Yes | No | Yes | Yes No | No | NA | Yes | Medium
Joo, 2017 ^21^ | Yes | Partial Yes | No | Partial Yes | Yes | Yes | NA | Yes | Medium
Le Berre, 2017 ^22^ | Yes | Yes | No | Yes | Yes | Yes | Yes | Yes | High
Moe, 2017 ^23^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Raven, 2016 ^24^ | Yes | Yes | No | Yes | No | Partial Yes | NA | Yes | Low
Smith, 2016 ^25^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Soril, 2015 ^26^ | Yes | Partial Yes | No | Yes | Yes | Yes | NA | Yes | High
Totten, 2016 ^30^ | Yes | Yes | Yes | Yes | Yes | Yes | NA | Yes | High
Van der Elst, 2018 ^27^ | Yes | Yes | No | Partial Yes | No Yes | Yes | Yes | Yes | Medium
Weeks, 2018 ^28^ | Yes | No | Yes | Yes | No | Yes | No | Yes | Low