# APPENDIX 3 STUDY SELECTION CRITERIA

| Inclusion Criteria | Exclusion Criteria
Population | Community-dwelling adults with a variety of ambulatory care sensitive conditions and/or at higher risk of having repeat hospitalization of emergency department [ED] visits | Restricted to single condition (eg, heart failure) or single combination (eg, diabetes and depression)
Intervention | Care coordination models:; - Care or case management; - Transitional care (if involving patient contact ≥ 1 month after discharge); - Home-based primary care; - Intensive primary care; - Integrated or interdisciplinary care; - Collaborative care model | Hospice and end-of-life care (if exclusive focus of intervention)
Comparator | Any (active or inactive)
Outcomes | - Primary—Hospitalization, ED visits; - Secondary—Patient experience; tools and approaches
Timing | Any duration
Setting | Community-base, outpatient
Study Design | - For KQ 1 & 2: Systematic review (SR) or Patient Level Meta-Analysis—must have search strategy, eligibility criteria, and analysis/synthesis plan; may include RCTs, observational studies, and/or qualitative studies; - For KQ 3&4: RCTs or quasi-experimental studies (eg, cohorts with comparative controls) | Expert or narrative reviews
Other | English Language