# APPENDIX 2 SEARCH STRATEGIES FOR PRIMARY STUDIES

## OVID MEDLINE AND EMBASE

1 | Exp Case Management/ or ((care or case) adj1 management).ti,ab.
2 | Exp transitional care/
3 | (home based primary care).ti,ab. or (home based primary care).kw. or (home based primary care).sh
4 | (intensive primary care).ti,ab. or (intensive primary care).kw. or (intensive primary care).sh.
5 | ((integrat* or collaborat* or coordinat* or transition* or interdisciplin*) adj1 care).ti,ab.
6 | (“delivery of health care, integrated” or “care continuity” or “continuum of care”).ti,ab.
7 | or/1-6
8 | Randomized Controlled Trials as Topic/
9 | randomized controlled trial.ti,ab,sh,kw,pt.
10 | random allocation.ti,ab.
11 | Double-Blind Method/
12 | Single-Blind Method/
13 | clinical trial/
14 | clinical trial, phase i.pt.
15 | clinical trial, phase ii.pt.
16 | clinical trial, phase iii.pt.
17 | clinical trial, phase iv.pt.
18 | controlled clinical trial.pt.
19 | clinical trial.pt.
20 | exp Clinical trials as topic/
21 | (clinical adj trial$).tw.
22 | ((singl$ or doubl$ or treb$ or tripl$) adj (blind$3 or mask$3)).tw.
23 | randomly allocated.tw.
24 | (allocated adj2 random$).tw.
25 | or/8-24
26 | 7 and 25
27 | Limit 26 to English
28 | Limit 27 to yr=”2018-current”
29 | Remove duplicates from 28

## CINAHL

1 | TI “care management” or TI “case management” OR AB “care management” or AB “case management”
2 | TI “transition* care” OR AB “transition* care”
3 | TI “home based primary care” OR AB “home based primary care”
4 | TI “intensive primary care” OR AB “intensive primary care”
5 | TI “integrat* care” OR AB “integrat* care”
6 | TI “care continuity” OR AB “care continuity”
7 | TI “continuum of care” OR AB “continuum of care”
8 | TI “collaborat* care” OR AB “collaborat* care”
9 | TI “coordinat* care” OR AB “coordinat* care”
10 | TI “care coordinat*” OR AB “care coordinat*”
11 | TI “interdisciplin* care” OR AB “interdisciplin* care”
12 | S1 OR S2 OR S3 OR S4 OR S5 OR S6 OR S7 OR S8 OR S9 OR S10 OR S11
13 | TI (randomized controlled trial or randomised controlled trial) OR AB (randomized controlled trial or randomised controlled trial)
14 | TI “random* allocat*” OR AB “random* allocat*”
15 | S13 OR S14
16 | S15 AND S12 (Limits applied: Peer reviewed; published 2018-current; English language; exclude MEDLINE records)