# APPENDIX 1 SEARCH STRATEGIES FOR SYSTEMATIC REVIEWS

## OVID MEDLINE

1 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (systematic review or literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-analysis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).mp.
2 | (case report or case series or letter or comment or editorial).tw.
3 | 1 not 2
4 | Exp Case Management/ or ((care or case) adj1 management).ti,ab.
5 | Exp transitional care/
6 | (home based primary care).ti,ab. or (home based primary care).kw. or (home based primary care).sh
7 | (intensive primary care).ti,ab. or (intensive primary care).kw. or (intensive primary care).sh.
8 | ((integrat* or collaborat* or coordinat* or transition* or interdisciplin*) adj1 care).ti,ab.
9 | or/4-8
10 | 3 and 9
11 | Limit 9 to English
12 | Limit 11 to yr=”2015-current”

## OVID EMBASE

1 | (meta-analy$ or metaanaly$ or meta analy$).tw. or exp Meta-Analysis/ or (systematic adj (review$ or overview$)).tw. or (systematic review or literature review or rapid review or umbrella review or meta synthesis or metasynthesis or meta-analysis or meta-synthesis or integrative review or data synthesis or comparative effectiveness review).mp.
2 | (case report or case series or letter or comment or editorial).tw.
3 | 1 not 2
4 | Exp Case Management/ or ((care or case) adj1 management).ti,ab.
5 | Exp transitional care/
6 | (home based primary care).ti,ab. or (home based primary care).kw. or (home based primary care).sh
7 | (intensive primary care).ti,ab. or (intensive primary care).kw. or (intensive primary care).sh.
8 | ((integrat* or collaborat* or coordinat* or transition* or interdisciplin*) adj1 care).ti,ab.
9 | or/4-8
10 | 3 and 9
11 | Limit 9 to English
12 | Limit 11 to yr=”2015-current”
13 | Limit 12 to conference abstract status
14 | 12 not 13

## CINAHL

1 | (TI (systematic* n3 review*)) or (AB (systematic* n3 review*)) or (TI (systematic* n3 literature)) or (AB (systematic* n3 literature)) or (TI (integrative n3 review)) or (AB (integrative n3 review)) or (TI (information n2 synthesis)) or (TI (data n2 synthesis)) or (AB (information n2 synthesis)) or (AB (data n2 synthesis)) or (TI (meta-analy* or metaanaly*)) or (AB (meta-analy* or metaanaly*)) or (TI (umbrella* n2 review*)) or (AB (umbrella* n2 review*)) or (TI (rapid* review*)) or (AB (rapid* review*)) or (TI (compar* effect* review)) or (AB (compar* effect* review))
2 | (TI (care or case) n2 management) or (AB (care or case) n2 management)
3 | (TI (transitional care)) or (AB (transitional care))
4 | (TI (home based primary care)) or (AB (home based primary care))
5 | (TI (intens* primary care)) or (AB (intens* primary care))
6 | (TI ((integrat* or collaborat* or coordinat* or transition* or interdisciplin*) n2 care)) or (AB ((integrat* or collaborat* or coordinat* or transition* or interdisciplin*) n2 care))
7 | MH transitional care
8 | MH case management
9 | S2 OR S3 OR S4 OR S5 OR S6 OR S7 OR S8
10 | S1 AND S9 (Limiters: Research article, peer reviewed, published 2015 and later, human, English language)

## COCHRANE REPORTS

1 | (“case management”):ti,ab,kw OR (“care management”):ti,ab,kw OR (“intensive primary care”):ti,ab,kw OR (transition* next care):ti,ab,kw OR (“home based primary care”):ti,ab,kw OR (integrat* next care):ti,ab,kw OR (collaborat* next care):ti,ab,kw OR (coordinat* next care):ti,ab,kw OR (transition* next care):ti,ab,kw OR (interdisciplin* next care):ti,ab,kw
2 | with Cochrane Library publication date from Jan 2015 to Oct 2019, in Cochrane Reviews

## AHRQ REPORTS

1 | Keyword search for: Care coordination, case management, care management, collaborative care, integrative care, transitional care, home-based primary care, intensive primary care
2 | Limited to 2015 and later

## VA ESP REPORTS

1 | Title search for: Care, case, coordin*, manage*, collab*, integrat*, transit*, home-based*, intens*, interd*
2 | Limited to 2015 and later