# REFERENCES

1 Bruggeman AR, Kamal AH, LeBlanc TW, Ma JD, Baracos VE, Roeland EJ. Cancer Cachexia: Beyond Weight Loss. J Oncol Pract. Nov 2016;12(11):1163–1171. doi:10.1200/jop.2016.016832 27858548
2 Baker Rogers J, Syed K, Minteer JF. Cachexia. StatPearls. StatPearls Publishing Copyright © 2024, StatPearls Publishing LLC.; 2024.
3 Nutrition in Cancer Care (PDQ®)–Health Professional Version. Updated November 2023. https://www.cancer.gov/about-cancer/treatment/side-effects/appetite-loss/nutrition-hp-pdq#_23_toc
4 Dev R. Measuring cachexia-diagnostic criteria. Ann Palliat Med. Jan 2019;8(1):24–32. doi:10.21037/apm.2018.08.07 30525765
5 Anker MS, Holcomb R, Muscaritoli M, . Orphan disease status of cancer cachexia in the USA and in the European Union: a systematic review. J Cachexia Sarcopenia Muscle. Feb 2019;10(1):22–34. doi:10.1002/jcsm.12402 30920776
6 Vaughan VC, Martin P, Lewandowski PA. Cancer cachexia: impact, mechanisms and emerging treatments. J Cachexia Sarcopenia Muscle. Jun 2013;4(2):95–109. doi:10.1007/s13539-012-0087-1 23097000
7 Song M, Zhang Q, Tang M, . Associations of low hand grip strength with 1 year mortality of cancer cachexia: a multicentre observational study. J Cachexia Sarcopenia Muscle. Dec 2021;12(6):1489–1500. doi:10.1002/jcsm.12778 34545711
8 Naito T, Okayama T, Aoyama T, . Unfavorable impact of cancer cachexia on activity of daily living and need for inpatient care in elderly patients with advanced non-small-cell lung cancer in Japan: a prospective longitudinal observational study. BMC Cancer. Nov 28 2017;17(1):800. doi:10.1186/s12885-017-3795-2 29183277
9 Arthur ST, Van Doren BA, Roy D, Noone JM, Zacherle E, Blanchette CM. Cachexia among US cancer patients. J Med Econ. Sep 2016;19(9):874–80. doi:10.1080/13696998.2016.1181640 27100202
10 Li X, Hu C, Zhang Q, . Cancer cachexia statistics in China. Precision Nutrition. 2022;1(1)
11 Gannavarapu BS, Lau SKM, Carter K, . Prevalence and Survival Impact of Pretreatment Cancer-Associated Weight Loss: A Tool for Guiding Early Palliative Care. J Oncol Pract. Apr 2018;14(4):e238–e250. doi:10.1200/jop.2017.025221 29466074
12 Ozorio GA, Barão K, Forones NM. Cachexia Stage, Patient-Generated Subjective Global Assessment, Phase Angle, and Handgrip Strength in Patients with Gastrointestinal Cancer. Nutr Cancer. Jul 2017;69(5):772–779. doi:10.1080/01635581.2017.1321130 28524706
13 Zhou T, Wang B, Liu H, . Development and validation of a clinically applicable score to classify cachexia stages in advanced cancer patients. J Cachexia Sarcopenia Muscle. Apr 2018;9(2):306–314. doi:10.1002/jcsm.12275. Epub 2018 Jan 25.29372594
14 Evans WJ, Morley JE, Argilés J, . Cachexia: a new definition. Clin Nutr. Dec 2008;27(6):793–9. doi:10.1016/j.clnu.2008.06.013 18718696
15 Martin L. Diagnostic criteria for cancer cachexia: data versus dogma. Curr Opin Clin Nutr Metab Care. May 2016;19(3):188–98. doi:10.1097/mco.0000000000000272 26945342
16 Chen XY, Zhang XZ, Ma BW, . A comparison of four common malnutrition risk screening tools for detecting cachexia in patients with curable gastric cancer. Nutrition. Feb 2020;70:110498. doi:10.1016/j.nut.2019.04.009. Epub 2019 Apr 26.31655470
17 Cao Z, Zhao K, Jose I, Hoogenraad NJ, Osellame LD. Biomarkers for Cancer Cachexia: A Mini Review. Int J Mol Sci. Apr 26 2021;22(9)doi:10.3390/ijms22094501
18 Zullig LL, Sims KJ, McNeil R, . Cancer Incidence Among Patients of the U.S. Veterans Affairs Health Care System: 2010 Update. Mil Med. Jul 2017;182(7):e1883–e1891. doi:10.7205/milmed-d-16-00371
19 Affairs UDoV. Veterans Health Administration. https://www.va.gov/health/aboutvha.asp
20 Affairs UDoV. National Oncology Program. https://www.cancer.va.gov/index.html
21 Roeland EJ, Bohlke K, Baracos VE, . Management of Cancer Cachexia: ASCO Guideline. J Clin Oncol. Jul 20 2020;38(21):2438–2453. doi:10.1200/jco.20.00611 32432946
22 Cosci F, Fava GA. Staging of mental disorders: systematic review. Psychother Psychosom. 2013;82(1):20–34. doi:10.1159/000342243 23147126
23 Grande AJ, Silva V, Sawaris Neto L, Teixeira Basmage JP, Peccin MS, Maddocks M. Exercise for cancer cachexia in adults. Cochrane Database Syst Rev. Mar 18 2021;3(3):Cd010804. doi:10.1002/14651858.CD010804.pub3 33735441
24 Hammond S, Erridge S, Mangal N, Pacchetti B, Sodergren MH. The Effect of Cannabis-Based Medicine in the Treatment of Cachexia: A Systematic Review and Meta-Analysis. Cannabis Cannabinoid Res. Dec 2021;6(6):474–487. doi:10.1089/can.2021.0048 34664988
25 Jin X, Xu XT, Tian MX, Dai Z. Omega-3 polyunsaterated fatty acids improve quality of life and survival, but not body weight in cancer cachexia: A systematic review and meta-analysis of controlled trials. Nutr Res. Nov 2022;107:165–178. doi:10.1016/j.nutres.2022.09.009 36283229
26 Mbeutcha A, Rouprêt M, Kamat AM, . Prognostic factors and predictive tools for upper tract urothelial carcinoma: a systematic review. World J Urol. Mar 2017;35(3):337–353. doi:10.1007/s00345-016-1826-2 27101100
27 Millar SC, Arnold JB, Thewlis D, Fraysse F, Solomon LB. A systematic literature review of tibial plateau fractures: What classifications are used and how reliable and useful are they? Injury. Mar 2018;49(3):473–490. doi:10.1016/j.injury.2018.01.025 29395219
28 Moore ZE, Patton D. Risk assessment tools for the prevention of pressure ulcers. Cochrane Database Syst Rev. Jan 31 2019;1(1):Cd006471. doi:10.1002/14651858.CD006471.pub4 30702158
29 Niels T, Tomanek A, Freitag N, Schumann M. Can Exercise Counteract Cancer Cachexia? A Systematic Literature Review and Meta-Analysis. Integr Cancer Ther. Jan–Dec 2020;19:1534735420940414. doi:10.1177/1534735420940414 32954861
30 Potter R, Probyn K, Bernstein C, Pincus T, Underwood M, Matharu M. Diagnostic and classification tools for chronic headache disorders: A systematic review. Cephalalgia. May 2019;39(6):761–784. doi:10.1177/0333102418806864 30335472
31 Rahman A, O’Connor DB, Gather F, . Clinical Classification and Severity Scoring Systems in Chronic Pancreatitis: A Systematic Review. Dig Surg. 2020;37(3):181–191. doi:10.1159/000501429 31269496
32 Schiavo G, Forgerini M, Lucchetta RC, Mastroianni PC. A comprehensive look at explicit screening tools for potentially inappropriate medication: A systematic scoping review. Australas J Ageing. Sep 2022;41(3):357–382. doi:10.1111/ajag.13046 35226786
33 Simon L, Baldwin C, Kalea AZ, Slee A. Cannabinoid interventions for improving cachexia outcomes in cancer: a systematic review and meta-analysis. J Cachexia Sarcopenia Muscle. Feb 2022;13(1):23–41. doi:10.1002/jcsm.12861 34881518
34 Stevenson JM, Williams JL, Burnham TG, . Predicting adverse drug reactions in older adults; a systematic review of the risk prediction models. Clin Interv Aging. 2014;9:1581–93. doi:10.2147/cia.S65475 25278750
35 Stynes S, Konstantinou K, Dunn KM. Classification of patients with low back-related leg pain: a systematic review. BMC Musculoskelet Disord. May 23 2016;17:226. doi:10.1186/s12891-016-1074-z 27215590
36 Wang J, Wang Y, Tong M, Pan H, Li D. Medical Cannabinoids for Cancer Cachexia: A Systematic Review and Meta-Analysis. Biomed Res Int. 2019;2019:2864384. doi:10.1155/2019/2864384 31341892
37 Balduzzi S RG, Schwarzer G “How to perform a meta-analysis with R: a practical tutorial. Evidence-Based Mental Health. 2019:153–160.
38 Anderson LJ, Chong N, Migula D, . Muscle mass, not radiodensity, predicts physical function in cancer patients with or without cachexia. Oncotarget. 2020;11(20):1911–1921. doi:10.18632/oncotarget.27594 32499874
39 Du C, Wang C, Guan X, . Asprosin is associated with anorexia and body fat mass in cancer patients. Support Care Cancer. Mar 2021;29(3):1369–1375. doi:10.1007/s00520-020-05621-8. Epub 2020 Jul 13.32661697
40 Álvaro Sanz E, Abilés J, Garrido Siles M, Pérez Ruíz E, Alcaide García J, Rueda Domínguez A. Impact of weight loss on cancer patients’ quality of life at the beginning of the chemotherapy. Support Care Cancer. Feb 2021;29(2):627–634. doi:10.1007/s00520-020-05496-9. Epub 2020 May 18.32424642
41 Anderson LJ, Lee J, Mallen MC, . Evaluation of physical function and its association with body composition, quality of life and biomarkers in cancer cachexia patients. Clin Nutr. Mar 2021;40(3):978–986. doi:10.1016/j.clnu.2020.07.001. Epub 2020 Jul 15.32713720
42 Blauwhoff-Buskermolen S, Langius JA, Heijboer AC, Becker A, de van der Schueren MA, Verheul HM. Plasma Ghrelin Levels Are Associated with Anorexia but Not Cachexia in Patients with NSCLC. Front Physiol. 2017;8:119. doi:10.3389/fphys.2017.00119. eCollection 2017.28298897
43 Blauwhoff-Buskermolen S, Langius JAE, Becker A, Verheul HMW, de van der Schueren MAE. The influence of different muscle mass measurements on the diagnosis of cancer cachexia. J Cachexia Sarcopenia Muscle. Aug 2017;8(4):615–622. doi:10.1002/jcsm.12200. Epub 2017 Apr 26.28447434
44 Chen X, Zeng Y, Huang Y, . Preoperative Cachexia predicts poor outcomes in young rather than elderly gastric cancer patients: a prospective study. Cancer Manag Res. 2019;11:8101–8110. doi:10.2147/cmar.S213237. eCollection 2019.31564970
45 da Rocha IMG, Marcadenti A, de Medeiros GOC, . Is cachexia associated with chemotherapy toxicities in gastrointestinal cancer patients? A prospective study. J Cachexia Sarcopenia Muscle. Apr 2019;10(2):445–454. doi:10.1002/jcsm.12391. Epub 2019 Mar 28.30924270
46 De Waele E, Demol J, Caccialanza R, . Unidentified cachexia patients in the oncologic setting: Cachexia UFOs do exist. Nutrition. Jul–Aug 2019;63–64:200–204. doi:10.1016/j.nut.2019.02.015. Epub 2019 Feb 27.31029048
47 Deng M, Aberle MR, van Bijnen AAJHM, . Lipocalin-2 and neutrophil activation in pancreatic cancer cachexia. Frontiers in Immunology. 2023;14:1159411. doi:10.3389/fimmu.2023.1159411 37006254
48 Fukuta A, Saito T, Murata S, . Impact of preoperative cachexia on postoperative length of stay in elderly patients with gastrointestinal cancer. Nutrition. Feb 2019;58:65–68. doi:10.1016/j.nut.2018.06.022. Epub 2018 Oct 11.30316109
49 Gong C, Wan Q, Zhao R, Zuo X, Chen Y, Li T. Cachexia Index as a Prognostic Indicator in Patients with Gastric Cancer: A Retrospective Study. Cancers (Basel). Sep 10 2022;14(18)doi:10.3390/cancers14184400.
50 Hadzibegovic S, Porthun J, Lena A, . Hand grip strength in patients with advanced cancer: A prospective study. J Cachexia Sarcopenia Muscle. Jun 15 2023;doi:10.1002/jcsm.13248.
51 Hayashi N, Sato Y, Fujiwara Y, . Clinical Impact of Cachexia in Head and Neck Cancer Patients Who Received Chemoradiotherapy. Cancer Manag Res. 2021;13:8377–8385. doi:10.2147/cmar.S329581. eCollection 2021.34795523
52 Hou YC, Chen CY, Huang CJ, . The Differential Clinical Impacts of Cachexia and Sarcopenia on the Prognosis of Advanced Pancreatic Cancer. Cancers (Basel). Jun 26 2022;14(13)doi:10.3390/cancers14133137.
53 Huo Z, Chong F, Yin L, . Development and validation of an online dynamic nomogram system for predicting cancer cachexia among inpatients: a real-world cohort study in China. Support Care Cancer. Dec 22 2022;31(1):72. doi:10.1007/s00520-022-07540-2.36543973
54 Jones AJ, Davis KP, Novinger LJ, . Postoperative consequences of cancer cachexia after head and neck free flap reconstruction. Head Neck. Jul 2022;44(7):1665–1677. doi:10.1002/hed.27072. Epub 2022 Apr 29.35488469
55 LeBlanc TW, Nickolich M, Rushing CN, Samsa GP, Locke SC, Abernethy AP. What bothers lung cancer patients the most? A prospective, longitudinal electronic patient-reported outcomes study in advanced non-small cell lung cancer. Support Care Cancer. Dec 2015;23(12):3455–63. doi:10.1007/s00520-015-2699-4. Epub 2015 Mar 21.25791391
56 LeBlanc TW, Nipp RD, Rushing CN, . Correlation between the international consensus definition of the Cancer Anorexia-Cachexia Syndrome (CACS) and patient-centered outcomes in advanced non-small cell lung cancer. J Pain Symptom Manage. Apr 2015;49(4):680–9. doi:10.1016/j.jpainsymman.2014.09.008. Epub 2014 Nov 4.25461669
57 Liao WC, Chen PR, Huang CC, . Relationship between pancreatic cancer-associated diabetes and cachexia. J Cachexia Sarcopenia Muscle. Aug 2020;11(4):899–908. doi:10.1002/jcsm.12553. Epub 2020 Feb 25.32100478
58 Liu CA, Zhang Q, Ruan GT, . Novel Diagnostic and Prognostic Tools for Lung Cancer Cachexia: Based on Nutritional and Inflammatory Status. Front Oncol. 2022;12:890745. doi:10.3389/fonc.2022.890745. eCollection 2022.35898878
59 Loumaye A, De Barsy M, Nachit M, . Role of activin A and myostatin in human cancer cachexia. Journal of Clinical Endocrinology and Metabolism. 2015;100(5):2030–2038. doi:10.1210/jc.2014-4318 25751105
60 Luvián-Morales J, Castillo-Aguilar J, Delgadillo-González M, . Validation of the QLQ-CAX24 instrument in cervical cancer and its association with cachexia classifications. Jpn J Clin Oncol. Mar 30 2023;53(4):304–312. doi:10.1093/jjco/hyac199.36579766
61 Madeddu C, Busquets S, Donisi C, . Effect of Cancer-Related Cachexia and Associated Changes in Nutritional Status, Inflammatory Status, and Muscle Mass on Immunotherapy Efficacy and Survival in Patients with Advanced Non-Small Cell Lung Cancer. Cancers. 2023;15(4):1076. doi:10.3390/cancers15041076 36831431
62 Ohmae N, Yasui-Yamada S, Furumoto T, . Muscle mass, quality, and strength; physical function and activity; and metabolic status in cachectic patients with head and neck cancer. Clin Nutr ESPEN. Feb 2023;53:113–119. doi:10.1016/j.clnesp.2022.12.006. Epub 2022 Dec 9.36657901
63 Poisson J, Martinez-Tapia C, Heitz D, . Prevalence and prognostic impact of cachexia among older patients with cancer: a nationwide cross-sectional survey (NutriAgeCancer). J Cachexia Sarcopenia Muscle. Dec 2021;12(6):1477–1488. doi:10.1002/jcsm.12776. Epub 2021 Sep 14.34519440
64 Rounis K, Makrakis D, Tsigkas AP, . Cancer cachexia syndrome and clinical outcome in patients with metastatic non-small cell lung cancer treated with PD-1/PD-L1 inhibitors: results from a prospective, observational study. Transl Lung Cancer Res. Aug 2021;10(8):3538–3549. doi:10.21037/tlcr-21-460.34584855
65 Ruan GT, Yang M, Zhang XW, . Association of Systemic Inflammation and Overall Survival in Elderly Patients with Cancer Cachexia - Results from a Multicenter Study. J Inflamm Res. 2021;14:5527–5540. doi:10.2147/jir.S332408. eCollection 2021.34737602
66 Ruan GT, Zhang Q, Zhang X, . Geriatric Nutrition Risk Index: Prognostic factor related to inflammation in elderly patients with cancer cachexia. J Cachexia Sarcopenia Muscle. Dec 2021;12(6):1969–1982. doi:10.1002/jcsm.12800. Epub 2021 Sep 29.34585849
67 Schwarz S, Prokopchuk O, Esefeld K, . The clinical picture of cachexia: a mosaic of different parameters (experience of 503 patients). BMC Cancer. Feb 14 2017;17(1):130. doi:10.1186/s12885-017-3116-9.28193264
68 Shen XD, Wang X, Zheng ZJ, . The differential effects of sarcopenia and cachexia on overall survival for pancreatic ductal adenocarcinoma patients following pancreatectomy: A retrospective study based on a large population. Cancer Med. May 2023;12(9):10438–10448. doi:10.1002/cam4.5779. Epub 2023 Mar 20.36938648
69 Song M, Zhang Q, Liu T, . Efficacy of Global Leadership Initiative on Malnutrition as potential cachexia screening tool for patients with solid cancer. Nutr J. Dec 7 2022;21(1):73. doi:10.1186/s12937-022-00829-2.36476477
70 Srdic D, Plestina S, Sverko-Peternac A, Nikolac N, Simundic AM, Samarzija M. Cancer cachexia, sarcopenia and biochemical markers in patients with advanced non-small cell lung cancer-chemotherapy toxicity and prognostic value. Support Care Cancer. Nov 2016;24(11):4495–502. doi:10.1007/s00520-016-3287-y. Epub 2016 May 28.27236439
71 Stene GB, Balstad TR, Leer ASM, . Deterioration in Muscle Mass and Physical Function Differs According to Weight Loss History in Cancer Cachexia. Cancers (Basel). Dec 3 2019;11(12)doi:10.3390/cancers11121925.
72 Sullivan ES, Daly LE, Scannell C, . A large, multi-centre prospective study demonstrating high prevalence of malnutrition associated with reduced survival in ambulatory systemic anti-cancer therapy patients. Clin Nutr ESPEN. Dec 2022;52:208–217. doi:10.1016/j.clnesp.2022.10.009. Epub 2022 Oct 25.36513456
73 Sun L, Quan XQ, Yu S. An Epidemiological Survey of Cachexia in Advanced Cancer Patients and Analysis on Its Diagnostic and Treatment Status. Nutr Cancer. 2015;67(7):1056–62. doi:10.1080/01635581.2015.1073753. Epub 2015 Aug 28.26317149
74 Suno M, Endo Y, Nishie H, Kajizono M, Sendo T, Matsuoka J. Refractory cachexia is associated with increased plasma concentrations of fentanyl in cancer patients. Ther Clin Risk Manag. 2015;11:751–7. doi:10.2147/tcrm.S79374. eCollection 2015.26056457
75 Tan S, Xu J, Wang J, . Development and validation of a cancer cachexia risk score for digestive tract cancer patients before abdominal surgery. J Cachexia Sarcopenia Muscle. Apr 2023;14(2):891–902. doi:10.1002/jcsm.13207. Epub 2023 Mar 7.36880286
76 Thoresen L, Frykholm G, Lydersen S, . Nutritional status, cachexia and survival in patients with advanced colorectal carcinoma. Different assessment criteria for nutritional status provide unequal results. Clin Nutr. Feb 2013;32(1):65–72. doi:10.1016/j.clnu.2012.05.009. Epub 2012 Jun 12.22695408
77 van der Werf A, van Bokhorst QNE, de van der Schueren MAE, Verheul HMW, Langius JAE. Cancer Cachexia: Identification by Clinical Assessment versus International Consensus Criteria in Patients with Metastatic Colorectal Cancer. Nutr Cancer. Nov–Dec 2018;70(8):1322–1329. doi:10.1080/01635581.2018.1504092. Epub 2018 Sep 20.30235002
78 Vanhoutte G, van de Wiel M, Wouters K, . Cachexia in cancer: what is in the definition? BMJ Open Gastroenterol. 2016;3(1):e000097. doi:10.1136/bmjgast-2016-000097. eCollection 2016.
79 Wallengren O, Lundholm K, Bosaeus I. Diagnostic criteria of cancer cachexia: relation to quality of life, exercise capacity and survival in unselected palliative care patients. Support Care Cancer. Jun 2013;21(6):1569–77. doi:10.1007/s00520-012-1697-z. Epub 2013 Jan 13.23314651
80 Wan Q, Yuan Q, Zhao R, . Prognostic value of cachexia index in patients with colorectal cancer: A retrospective study. Front Oncol. 2022;12:984459. doi:10.3389/fonc.2022.984459 36212479
81 Wesseltoft-Rao N, Hjermstad MJ, Ikdahl T, . Comparing two classifications of cancer cachexia and their association with survival in patients with unresected pancreatic cancer. Nutr Cancer. 2015;67(3):472–80. doi:10.1080/01635581.2015.1004728 25710201
82 Willemsen ACH, De Moor N, Van Dessel J, . The predictive and prognostic value of weight loss and body composition prior to and during immune checkpoint inhibition in recurrent or metastatic head and neck cancer patients. Cancer Med. Apr 2023;12(7):7699–7712. doi:10.1002/cam4.5522. Epub 2022 Dec 9.36484469
83 Willemsen ACH, Pilz W, Hoeben A, Hoebers FJP, Schols A, Baijens LWJ. Oropharyngeal dysphagia and cachexia: Intertwined in head and neck cancer. Head Neck. Apr 2023;45(4):783–797. doi:10.1002/hed.27288. Epub 2022 Dec 30.36583567
84 Xie H, Ruan G, Wei L, . Hand grip strength-based cachexia index as a predictor of cancer cachexia and prognosis in patients with cancer. J Cachexia Sarcopenia Muscle. Feb 2023;14(1):382–390. doi:10.1002/jcsm.13139. Epub 2022 Nov 29.36447437
85 Yin L, Cui J, Lin X, . Identifying cancer cachexia in patients without weight loss information: machine learning approaches to address a real-world challenge. Am J Clin Nutr. Nov 2022;116(5):1229–1239. doi:10.1093/ajcn/nqac251. Epub 2023 Feb 10.36095136
86 Zhou D, Zhang Y, Mamtawla G, . Iron overload is related to muscle wasting in patients with cachexia of gastric cancer: using quantitative proteome analysis. Medical Oncology. 2020;37(12):113. doi:10.1007/s12032-020-01439-w 33196891
87 Zhuang CL, Dong QT, Shi HP, . Cachexia Versus Sarcopenia in Clinical Characteristics and Prognostic Value After Radical Gastrectomy for Gastric Cancer: A Large-Scale Prospective Study. Ann Surg Oncol. Apr 2022;29(4):2348–2358. doi:10.1245/s10434-021-11084-w. Epub 2021 Nov 19.34797480
88 Zopf Y, Schink K, Reljic D, . Assessing cachexia in older patients: Different definitions - But which one is the most practical for clinical routine? Archives of Gerontology and Geriatrics. 2020;86:103943. doi:10.1016/j.archger.2019.103943 31561063
89 Aktas A, Lorton CM, Griffin O, . Application of the 2011 international consensus cancer cachexia classification in routine oncology dietetic practice: An observational study. Nutr Clin Pract. Aug 2023;38(4):790–797. doi:10.1002/ncp.10915. Epub 2022 Nov 9.36351572
90 Antoun S, Morel H, Souquet PJ, . Staging of nutrition disorders in non-small-cell lung cancer patients: utility of skeletal muscle mass assessment. J Cachexia Sarcopenia Muscle. Aug 2019;10(4):782–793. doi:10.1002/jcsm.12418. Epub 2019 Apr 1.30932365
91 Bye A, Wesseltoft-Rao N, Iversen PO, . Alterations in inflammatory biomarkers and energy intake in cancer cachexia: a prospective study in patients with inoperable pancreatic cancer. Med Oncol. Jun 2016;33(6):54. doi:10.1007/s12032-016-0768-2. Epub 2016 Apr 27.27119533
92 Cavalcante Martins FF, de Pinho NB, de Carvalho Padilha P, . Patient-generated subjective global assessment predicts cachexia and death in patients with head, neck and abdominal cancer: A retrospective longitudinal study. Clin Nutr ESPEN. Jun 2019;31:17–22. doi:10.1016/j.clnesp.2019.03.013. Epub 2019 Apr 5.31060829
93 ÉB NB, Daly LE, Power DG, Cushen SJ, MacEneaney P, Ryan AM. Computed tomography diagnosed cachexia and sarcopenia in 725 oncology patients: is nutritional screening capturing hidden malnutrition? J Cachexia Sarcopenia Muscle. Apr 2018;9(2):295–305. doi:10.1002/jcsm.12258. Epub 2017 Dec 21.29271097
94 Gumpper-Fedus K, Hart PA, Belury MA, . Altered Plasma Fatty Acid Abundance Is Associated with Cachexia in Treatment-Naive Pancreatic Cancer. Cells. 2022;11(5):910. doi:10.3390/cells11050910 35269531
95 Jager-Wittenaar H, Dijkstra PU, Dijkstra G, . High prevalence of cachexia in newly diagnosed head and neck cancer patients: An exploratory study. Nutrition. Mar 2017;35:114–118. doi:10.1016/j.nut.2016.11.008. Epub 2016 Dec 14.28241978
96 Johns N, Hatakeyama S, Stephens NA, . Clinical classification of cancer cachexia: phenotypic correlates in human skeletal muscle. PLoS One. 2014;9(1):e83618. doi:10.1371/journal.pone.0083618. eCollection 2014.24404136
97 Johns N, Stretch C, Tan BH, . New genetic signatures associated with cancer cachexia as defined by low skeletal muscle index and weight loss. J Cachexia Sarcopenia Muscle. Feb 2017;8(1):122–130. doi:10.1002/jcsm.12138. Epub 2016 Aug 5.27897403
98 Morikawa A, Naito T, Sugiyama M, . Impact of Cancer Cachexia on Hospitalization-associated Physical Inactivity in Elderly Patients with Advanced Non-small-cell Lung Cancer. Asia Pac J Oncol Nurs. Oct–Dec 2018;5(4):377–382. doi:10.4103/apjon.apjon_20_18.30271819
99 Op den Kamp CM, Langen RC, Snepvangers FJ, . Nuclear transcription factor κ B activation and protein turnover adaptations in skeletal muscle of patients with progressive stages of lung cancer cachexia. Am J Clin Nutr. Sep 2013;98(3):738–48. doi:10.3945/ajcn.113.058388. Epub 2013 Jul 31.23902785
100 Penafuerte CA, Gagnon B, Sirois J, Murphy J, MacDonald N, Tremblay ML. Identification of neutrophil-derived proteases and angiotensin II as biomarkers of cancer cachexia. Br J Cancer. Mar 15 2016;114(6):680–7. doi:10.1038/bjc.2016.3. Epub 2016 Mar 8.26954714
101 Solís-Martínez O, Álvarez-Altamirano K, Cardenas D, Trujillo-Cabrera Y, Fuchs-Tarlovsky V. Cancer Cachexia Affects Patients with Head and Neck Cancer in All Stages of Disease: A Prospective Cross-Sectional Study. Nutr Cancer. 2022;74(1):82–89. doi:10.1080/01635581.2020.1869792. Epub 2021 Jan 16.33455464
102 van der Meij BS, Schoonbeek CP, Smit EF, Muscaritoli M, van Leeuwen PA, Langius JA. Pre-cachexia and cachexia at diagnosis of stage III non-small-cell lung carcinoma: an exploratory study comparing two consensus-based frameworks. Br J Nutr. Jun 28 2013;109(12):2231–9. doi:10.1017/s0007114512004527. Epub 2012 Nov 16.23153477
103 Akaoka M, Haruki K, Taniai T, . Clinical significance of cachexia index in patients with hepatocellular carcinoma after hepatic resection. Surg Oncol. Dec 2022;45:101881. doi:10.1016/j.suronc.2022.101881. Epub 2022 Nov 3.36371905
104 Aslan V, Kılıç ACK, Sütcüoğlu O, . Cachexia index in predicting outcomes among patients receiving immune checkpoint inhibitor treatment for metastatic renal cell carcinoma. Urol Oncol. Nov 2022;40(11):494.e1–494.e10. doi:10.1016/j.urolonc.2022.07.018. Epub 2022 Sep 20.
105 Demirelli B, Babacan NA, Ercelep Ö, . Modified Glasgow Prognostic Score, Prognostic Nutritional Index and ECOG Performance Score Predicts Survival Better than Sarcopenia, Cachexia and Some Inflammatory Indices in Metastatic Gastric Cancer. Nutr Cancer. 2021;73(2):230–238. doi:10.1080/01635581.2020.1749290. Epub 2020 Apr 9.32270713
106 Go SI, Park MJ, Lee GW. Clinical significance of the cachexia index in patients with small cell lung cancer. BMC Cancer. May 17 2021;21(1):563. doi:10.1186/s12885-021-08300-x.34001060
107 Go SI, Park MJ, Park S, . Cachexia index as a potential biomarker for cancer cachexia and a prognostic indicator in diffuse large B-cell lymphoma. J Cachexia Sarcopenia Muscle. Dec 2021;12(6):2211–2219. doi:10.1002/jcsm.12837. Epub 2021 Oct 21.34676685
108 Goh MJ, Kang W, Jeong WK, . Prognostic significance of cachexia index in patients with advanced hepatocellular carcinoma treated with systemic chemotherapy. Sci Rep. May 10 2022;12(1):7647. doi:10.1038/s41598-022-11736-1.35538112
109 Hamura R, Haruki K, Shirai Y, . Preoperative cachexia index can predict the prognosis of extrahepatic biliary tract cancer after resection. Surg Oncol. Sep 2022;44:101825. doi:10.1016/j.suronc.2022.101825. Epub 2022 Jul 31.35947886
110 Jafri SH, Previgliano C, Khandelwal K, Shi R. Cachexia Index in Advanced Non-Small-Cell Lung Cancer Patients. Clin Med Insights Oncol. 2015;9:87–93. doi:10.4137/cmo.S30891 26604850
111 Kamada T, Haruki K, Nakashima K, . Prognostic significance of the cachexia index in patients with stage I-III colorectal cancer who underwent laparoscopic surgery. Surg Today. Feb 1 2023;doi:10.1007/s00595-023-02646-4.
112 Karmali R, Alrifai T, Fughhi IAM, . Impact of cachexia on outcomes in aggressive lymphomas. Ann Hematol. Jun 2017;96(6):951–956. doi:10.1007/s00277-017-2958-1. Epub 2017 Apr 17.28417157
113 Nakashima K, Haruki K, Kamada T, . Usefulness of the cachexia index as a prognostic indicator for patients with gastric cancer. Annals of Gastroenterological Surgery. 2023;doi:10.1002/ags3.12669
114 Shimagaki T, Sugimachi K, Mano Y, . Cachexia index as a prognostic predictor after resection of pancreatic ductal adenocarcinoma. Annals of Gastroenterological Surgery. 2023;doi:10.1002/ags3.12686
115 Takano Y, Kodera K, Tsukihara S, . Association of a newly developed Cancer Cachexia Score with survival in Stage I-III colorectal cancer. Langenbecks Arch Surg. Apr 12 2023;408(1):145. doi:10.1007/s00423-023-02883-8.37043018
116 Tanji Y, Furukawa K, Haruki K, . Significant impact of cachexia index on the outcomes after hepatic resection for colorectal liver metastases. Annals of Gastroenterological Surgery. 2022;6(6):804–812. doi:10.1002/ags3.12578 36338593
117 Chen HW, Chen YC, Yang LH, . Impact of cachexia on oncologic outcomes of sarcopenic patients with upper tract urothelial carcinoma after radical nephroureterectomy. PLoS One. 2021;16(4):e0250033. doi:10.1371/journal.pone.0250033. eCollection 2021.33882095
118 Cong M, Song C, Xu H, . The patient-generated subjective global assessment is a promising screening tool for cancer cachexia. BMJ Support Palliat Care. May 2022;12(e1):e39–e46. doi:10.1136/bmjspcare-2020-002296. Epub 2020 Aug 21.
119 Kwon M, Kim RB, Roh JL, . Prevalence and clinical significance of cancer cachexia based on time from treatment in advanced-stage head and neck squamous cell carcinoma. Head Neck. Apr 2017;39(4):716–723. doi:10.1002/hed.24672. Epub 2016 Dec 21.28000343
120 Morimoto K, Uchino J, Yokoi T, . Impact of cancer cachexia on the therapeutic outcome of combined chemoimmunotherapy in patients with non-small cell lung cancer: a retrospective study. Oncoimmunology. 2021;10(1):1950411. doi:10.1080/2162402x.2021.1950411. eCollection 2021.34290909
121 Vigano AAL, Del Fabbro E, Bruera E, Borod M. The cachexia clinic: From staging to managing nutritional and functional problems in advanced cancer patients. Critical Reviews in Oncogenesis. 2012;17(3):293–304. doi:10.1615/CritRevOncog.v17.i3.70 22831160
122 White R, Weekes CE, Grant R, Baldwin C, Ahmed H. Determining the prevalence and severity of cancer cachexia in advanced non-small cell lung cancer and its relationship with chemotherapy outcomes. Support Care Cancer. Sep 2020;28(9):4373–4380. doi:10.1007/s00520-019-05259-1. Epub 2020 Jan 8.31916005
123 Wiegert EVM, de Oliveira LC, Calixto-Lima L, Mota ESLMSD, Peres WAF. Cancer cachexia: Comparing diagnostic criteria in patients with incurable cancer. Nutrition. Nov–Dec 2020;79–80:110945. doi:10.1016/j.nut.2020.110945 32927241
124 Fearon KC, Voss AC, Hustead DS. Definition of cancer cachexia: effect of weight loss, reduced food intake, and systemic inflammation on functional status and prognosis. Am J Clin Nutr. Jun 2006;83(6):1345–50. doi:10.1093/ajcn/83.6.1345.16762946
125 Argilés JM, Betancourt A, Guàrdia-Olmos J, . Validation of the CAchexia SCOre (CASCO). Staging Cancer Patients: The Use of miniCASCO as a Simplified Tool. Front Physiol. 2017;8:92. doi:10.3389/fphys.2017.00092 28261113
126 Ballyuzek MF, Mashkova MV, Arutjunyan AV, Duke VA. [Melatonin as a marker of the grade of cardiac disorders during cachexia development in oncological patients of different ages]. Adv Gerontol. 2017;30(1):70–77.28557393
127 Argilés JM, López-Soriano FJ, Toledo M, Betancourt A, Serpe R, Busquets S. The cachexia score (CASCO): a new tool for staging cachectic cancer patients. J Cachexia Sarcopenia Muscle. Jun 2011;2(2):87–93. doi:10.1007/s13539-011-0027-5 21766054
128 Ueshima J, Maeda K, Shimizu A, . Cachexia staging score predicts survival in patients with cancer who receive palliative care. Nutrition. Feb 2023;106:111880. doi:10.1016/j.nut.2022.111880 36436335
129 Yi H, Wang Y, Liang Q, Li X, Chen C, Mao X. R-CSS: A clinically applicable score to classify cachexia stages in patients with cancer undergoing intensity-modulated radiation therapy. Asia Pac J Oncol Nurs. Jan 2023;10(1):100164. doi:10.1016/j.apjon.2022.100164. eCollection 2023 Jan.36655012
130 Wang J, Tan S, Xu J, . Development and application of the Cancer Cachexia Staging Index for the diagnosis and staging of cancer cachexia. Nutrition. Jun 4 2023;114:112114. doi:10.1016/j.nut.2023.112114.37454609
131 Gabison R, Gibbs M, Uziely B, Ganz FD. The cachexia assessment scale: Development and psychometric properties. Oncology Nursing Forum. 2010;37(5):635–640. doi:10.1188/10.ONF.635-640 20797955
132 de Oliveira LC, Rosa K, Gaspar T, Paiva BSR, Paiva CE, Peres WAF. Clinical usefulness of the Patient-Generated Subjective Global Assessment and modified Glasgow Prognostic Score in decision making concerning the indication of enteral nutritional therapy in patients with incurable cancer receiving palliative care. Nutrition. Aug 2023;112:112057. doi:10.1016/j.nut.2023.112057. Epub 2023 Apr 24.37224572
133 Fukushima T, Nakano J, Ishii S, . Characteristics of muscle function and the effect of cachexia in patients with haematological malignancy. Eur J Cancer Care (Engl). Mar 2019;28(2):e12956. doi:10.1111/ecc.12956. Epub 2018 Oct 25.30357948
134 Matsuzuka T, Suzuki M, Saijoh S, . [Assessment of Cachexia in Head and Neck Cancer Patients Based on a Modified Glasgow Prognostic Score]. Nihon Jibiinkoka Gakkai Kaiho. Feb 2016;119(2):125–8. doi:10.3950/jibiinkoka.119.125.27149710
135 Naito T, Tashiro M, Ishida T, Ohnishi K, Kawakami J. Cancer cachexia raises the plasma concentration of oxymorphone through the reduction of CYP3A but not CYP2D6 in oxycodone-treated patients. J Clin Pharmacol. Aug 2013;53(8):812–8. doi:10.1002/jcph.112. Epub 2013 Jun 3.23733622
136 Silva GAD, Wiegert EVM, Calixto-Lima L, Oliveira LC. Clinical utility of the modified Glasgow Prognostic Score to classify cachexia in patients with advanced cancer in palliative care. Clin Nutr. May 2020;39(5):1587–1592. doi:10.1016/j.clnu.2019.07.002. Epub 2019 Jul 20.31377013
137 Cavka L, Pohar Perme M, Rotovnik Kozjek N, Seruga B. Prognostic Impact of Nutritional Status on Overall Survival and Health-Related Quality of Life in Men with Advanced Prostate Cancer. Nutrients. Feb 20 2023;15(4)doi:10.3390/nu15041044.
138 V IJ-H, Heerschop S, Wanten G, van den Berg M. Evaluation of the Validity and Feasibility of the GLIM Criteria Compared with PG-SGA to Diagnose Malnutrition in Relation to One-Year Mortality in Hospitalized Patients. J Acad Nutr Diet. Mar 2022;122(3):595–601. doi:10.1016/j.jand.2021.07.011 34463257
139 Jager-Wittenaar H, Ottery FD. Assessing nutritional status in cancer: role of the Patient-Generated Subjective Global Assessment. Curr Opin Clin Nutr Metab Care. Sep 2017;20(5):322–329. doi:10.1097/mco.0000000000000389 28562490
140 Arends J, Strasser F, Gonella S, . Cancer cachexia in adult patients: ESMO Clinical Practice Guidelines(☆). ESMO Open. Jun 2021;6(3):100092. doi:10.1016/j.esmoop.2021.100092 34144781
141 Takahashi K, Masuda T, Ishikawa Y, . A Novel Frailty Grade Combined with Cachexia Index and Osteopenia in Esophagectomy. World J Surg. Jun 2023;47(6):1503–1511. doi:10.1007/s00268-023-06942-5. Epub 2023 Feb 21.36802232
142 Go SI, Kim HG, Kang MH, Park S, Lee GW. Prognostic model based on the geriatric nutritional risk index and sarcopenia in patients with diffuse large B-cell lymphoma. BMC Cancer. May 18 2020;20(1):439. doi:10.1186/s12885-020-06921-2.32423395
143 Namikawa T, Marui A, Yokota K, . Frequency and prognostic impact of cachexia during drug treatment for unresectable advanced gastric cancer patients. Surg Today. Nov 2022;52(11):1560–1567. doi:10.1007/s00595-022-02493-9. Epub 2022 Mar 24.35322296
144 Orell-Kotikangas H, Österlund P, Mäkitie O, . Cachexia at diagnosis is associated with poor survival in head and neck cancer patients. Acta Otolaryngol. Jul 2017;137(7):778–785. doi:10.1080/00016489.2016.1277263. Epub 2017 Jan 26.28125312
145 Wiegert EVM, de Oliveira LC, Calixto-Lima L, Chaves GV, Silva Lopes MS, Peres WAF. New cancer cachexia staging system for use in clinical practice. Nutrition. Oct 2021;90:111271. doi:10.1016/j.nut.2021.111271 34004417
146 Muscaritoli M, Imbimbo G, Jager-Wittenaar H, . Disease-related malnutrition with inflammation and cachexia. Clin Nutr. Aug 2023;42(8):1475–1479. doi:10.1016/j.clnu.2023.05.013 37302879
147 Meza-Valderrama D, Marco E, Dávalos-Yerovi V, . Sarcopenia, Malnutrition, and Cachexia: Adapting Definitions and Terminology of Nutritional Disorders in Older People with Cancer. Nutrients. Feb 26 2021;13(3)doi:10.3390/nu13030761
148 Dunne RF, Loh KP, Williams GR, Jatoi A, Mustian KM, Mohile SG. Cachexia and Sarcopenia in Older Adults with Cancer: A Comprehensive Review. Cancers (Basel). Nov 25 2019;11(12)doi:10.3390/cancers11121861
149 Ueshima J, Inoue T, Saino Y, . Diagnosis and prevalence of cachexia in Asians: A scoping review. Nutrition. Mar 2024;119:112301. doi:10.1016/j.nut.2023.112301 38113614
150 Chowdhry SM, Chowdhry VK. Cancer cachexia and treatment toxicity. Curr Opin Support Palliat Care. Dec 2019;13(4):292–297. doi:10.1097/spc.0000000000000450 31389845
151 Andreyev HJ, Norman AR, Oates J, Cunningham D. Why do patients with weight loss have a worse outcome when undergoing chemotherapy for gastrointestinal malignancies? Eur J Cancer. Mar 1998;34(4):503–9. doi:10.1016/s0959-8049(97)10090-9 9713300
152 Coles TM, Wilson SM, Kim B, Beckham JC, Kinghorn WA. From obligation to opportunity: future of patient-reported outcome measures at the Veterans Health Administration. Transl Behav Med. Nov 25 2019;9(6):1157–1162. doi:10.1093/tbm/ibz121 31348511