# DISCUSSION

We identified 114 studies that described 32 unique algorithms to diagnose or stage cachexia. Of the 32 algorithms, 22 were compared to a clinical exam or against the Fearon 2011 algorithm, 5 compared results to another cachexia algorithm, and 1 compared the developed algorithm to several existing algorithms (including Fearon 2011). Forty-nine studies evaluated the adjusted association between cachexia and a prioritized outcome in analyses. Across the 32 algorithms, anorexia, appetite, or nutrition; sarcopenia; and weight loss, BMI, and albumin were the most commonly used components, but there were more than 20 different components used across all algorithms. The most frequently evaluated outcomes were related to survival. Few studies reported on function, hospitalization, or cachexia symptom burden. Key findings include the following:

## Key Findings

- The most frequently evaluated algorithms included the Fearon 2011, the Cachexia Index, and Evans 2008 algorithms.
- Twenty-two algorithms were compared against a clinical exam or another cachexia algorithm in 23 studies. Fearon 2011 was used as a comparison algorithm in 17 of these studies.
- Fearon 2011, Cachexia Index, and Evans 2008 algorithms found worse survival outcomes for people with cachexia compared to those without cachexia. Among other algorithms, the majority found worse survival in cachectic compared to noncachectic patients.
- The cachexia algorithms that categorized patients by severity, including the Glasgow Prognostic Score, Cancer Cachexia Score, Cancer Cachexia Staging Index, Vigano 2017 algorithm, Cachexia Staging System, and Cachexia Staging Score, found worse survival outcomes in those with more severe cachexia compared to less severe cachexia.
- Patients with cachexia based on the Fearon 2011 criteria had longer hospital and ICU stays.
- There may not be a difference in survival outcomes between precachectic and noncachectic populations.
- There was sparse reporting of outcomes relating to function, hospitalization, and cachexia symptom burden. No studies reported outcomes of cachexia progression or feeding tube placement.
- Worse overall mortality is predicted by the Evans 2008 algorithm, Fearon 2006 algorithm, or CXI compared to the Fearon 2011 algorithm.

A recent systematic review estimated that as many as half of cancer patients in the US develop cachexia,^5^ but in practice diagnosing cachexia is difficult. There is great clinical interest in being able to prospectively identify people at high risk of developing cachexia or in the early stages of the disorder. Complicating practice are the wide variety of cachexia definitions and algorithms described in medical literature. To improve measurement of cachexia requires consensus definitions with algorithms that are easy to implement in routine practice. Recent guidelines from the European Society for Medical Oncology state that a comprehensive cachexia assessment should include information about nutritional, metabolic, and functional status; nutritional barriers; gastrointestinal dysfunction; distress and quality of life; and cancer-related factors.^140^ However, we found the algorithms of cachexia described in the literature included only some of these criteria. For example, Fearon 2011, which was the most commonly reported algorithm, includes only information on weight loss, BMI, and sarcopenia, leaving out many of these assessment criteria. Further, while there have been recent efforts to distinguish cachexia from malnutrition or sarcopenia alone,^146,^ ^147^ the nuanced relationship between these syndromes was not always clear in the identified algorithms. Some algorithms assessing cachexia used only components to identify malnutrition or sarcopenia, while other algorithms included components to help distinguish cachexia from these conditions.

Five studies reported worse overall mortality when using the Evans 2008 algorithm, CXI, or Fearon 2006 compared to the Fearon 2011 algorithm. The Evans 2008, CXI, and Fearon 2006 algorithms each include components beyond weight to assess cachexia, such as markers of inflammation. The differences in the strength of these associations and the algorithms used underscore the need for careful consideration, not only of availability of components but also of the outcomes being targeted when selecting an algorithm to use to identify cachexia. Although survival is important, patients may value other outcomes (eg, quality of life). Studies did not systematically evaluate the association between other patient-centered outcomes and the algorithms. Understanding the ability of different algorithms to assess these patient-centered outcomes is important when selecting which may be best to use.

While 69% of the algorithms were empirically compared to a clinical exam or another cachexia algorithm, validating cachexia algorithms is challenging given the lack of a well-established gold standard or reference case. Cachexia prevalence varied widely based on algorithms used. For instance, 1 study found that 52% of patients were identified as cachectic using the Fearon algorithm, but only 9% of those same patients were cachectic when identified by clinical assessment.^77^ Another study comparing Fearon 2006, Fearon 2011, and Evans 2008 algorithms reported prevalence rates of 12% to 85% depending on the algorithm.^79^ Variation in measures or tools to assess individual components also made it challenging to evaluate algorithms. For example, across studies that used the Fearon 2011 algorithm, sarcopenia was measured by CT, BIA, MUAMA, DEXA, SARC-F, and other tools. Further, cutoffs for what was considered “sarcopenia” varied widely by study. For instance, a study comparing 3 different methods of measuring sarcopenia reported that in 241 patients, 13% of patients were identified as sarcopenic by MUAMA, but 59% of these same patients were identified as sarcopenic using CT, and 93% using BIA.^43^ While cost, burden, and availability of tools for measuring components are important considerations,^148^ the lack of consistency adds further complication to the identification of cachexia. Additionally, few of the included studies (that were not conducted in East Asia) provided detailed information about the racial makeup of study samples, but racial differences in body composition should also be considered when establishing component cutoffs, such as BMI.^149^

An important limitation of the evidence base is the sparse reporting of outcomes of interest to the operational partners. Most studies reported survival-related outcomes. No study reported feeding tube placement or cachexia progression outcomes, and few studies reported on function, hospitalizations, or cachexia symptom burden. Additionally, a large number of studies were excluded because they did not report adjusted associations between cachexia and outcomes (see Appendix). Some included studies adjusted for individual components of the cachexia algorithm which raised concerns of collinearity, and some studies adjusted for multiple definitions of cachexia in the same model.

## Strengths and Limitations of the Systematic Review Process

A strength of our review was the detailed coding of algorithm components, scoring functions, and definitions. Our approach to evaluating algorithms provides a foundation to understand nuanced scoring criteria beyond face level labels of the individual algorithm components (eg, BMI or weight loss). For example, sarcopenia was commonly included in the algorithms and our coding conveys how this measure was collected and incorporated within and across algorithms.

One limitation of this review relates to the terminology surrounding cachexia. In the literature, the term cachexia was sometimes used interchangeably with related syndromes, such as malnutrition or anorexia. We included only studies that explicitly used the term “cachexia” to avoid incorrectly including studies that were not specific to cachexia. Because of this approach, it is possible that we excluded studies that may have assessed cachexia but used a different term. Conversely, this approach may also have led to the inclusion of studies that did not explicitly distinguish between cachexia and other related conditions such as malnutrition or sarcopenia, since these terms may be used interchangeably in the literature. This review was intended to focus on classification algorithms that used >1 component, such as weight, to identify cachexia. However, for the Fearon 2011 algorithm, cachexia could be defined by either weight measures alone, or weight loss in combination with sarcopenia. It is possible that patients included in these studies were identified as cachectic based solely on weight measures. As mentioned, the assessment of many components, such as sarcopenia or SMI, was not uniform across studies, even across studies using the same algorithm. The variation in the measurement of these criteria made comparing outcomes across studies challenging. Further, for some assessment tools, such as the CXI, we had to use study-specific cutoffs for cachexia classifications, which may make these definitions less applicable to other external samples. Additionally, while necessary in order to reduce any potential confounding between groups, our choice to only include studies that adjusted for confounding limited the number of studies and type of outcomes included in our analyses of the association between algorithms and outcomes, but by doing so, we excluded studies with clear confounder bias.

## IMPLICATIONS FOR VA POLICY AND PRACTICE

VA diagnoses over 50,000 Veterans with cancer annually^18^ and has made significant investments to deliver the most effective treatments to Veterans regardless of their location through cancer genomics, tele-oncology, and clinical trials. More broadly, the advent of immunotherapies and other targeted therapies has led to rapid advances in treating cancers that, until relatively recently, were considered untreatable. For people with cachexia, the accompanying weight loss, functional decline, and malnutrition hamper their ability to tolerate treatments and associated adverse effects.^150,^ ^151^ As VA continues to invest in oncology programs, collecting patient-reported outcomes (and cachexia factors) such as anorexia, fatigue, and quality of life could inform both oncologic and cachexia end points. Among the studies we identified, only 2 were conducted within the VA and both reported on the Fearon 2011 algorithm. The components of other well-performing cachexia algorithms (eg, weight loss, sarcopenia, anorexia) can by readily measured among VA patients with cancer. However, it is important to note that nearly 40% of available studies were conducted in China or Japan, which may limit the generalizability of evidence on the contribution of each component to algorithm performance.

Systematic collection of cachexia-related data is a necessary but complex task in a busy clinical environment, with implications for both front-line health care staff and VA’s data infrastructure. For example, weight loss can be obtained from the VA medical record. In contrast, anorexia and functional decline are neither systematically measured in Veterans nor stored in a common location in the VA electronic medical record. Thus, implementation of a standardized cachexia measure would require VA leadership support, development of the collection infrastructure, education of the oncology field, and the monitoring/re-enforcement of the importance of collection. Alongside these steps, it will likely be valuable to implement predictive analytics to identify those Veterans most at risk for cachexia and focus assessments on them.

Effective management of cachexia requires timely identification. The importance of identifying cachexia early and by severity is also highlighted by the role of emerging therapeutics. Few studies reported on patient quality of life or function, which are measures that may be sensitive to health system features. Again, this represents an opportunity for VA, which has the capability of collecting patient-reported outcomes and other measures.^152^ Being able to uniformly collect these data points could help improve understanding and identification of cachexia.

## FUTURE RESEARCH

While a variety of cachexia algorithms have been reported, few studies directly compared cachexia algorithms. Direct comparisons are needed to understand which algorithm may be best for early identification of cachexia patient outcomes. Future studies should be explicitly designed to compare algorithms and evaluate outcomes using propensity score or regression adjustment methods that control for known and potential sources of confounding. There is also a need to validate algorithms against, at minimum, an agreed upon reference standard (eg, Fearon 2011), and to validate these within specific populations, such as Veterans. This includes validation of biomarkers and other surrogate end points. Most cachexia classification algorithms included only 2 stages (presence or absence of cachexia), and there is a need to expand research on algorithms that more finely characterize cachexia severity and outcomes associated with cachexia severity. Few studies reported prioritized outcomes of interest. While survival outcomes based on cachexia status are of interest, other more modifiable outcomes such as patient quality of life or functional status should be included in future studies to clarify the impact of cachexia and cachexia interventions on these outcomes. Further, clinically meaningful outcomes should be considered when developing future algorithms. Finally, if new algorithms are developed, these should take a comprehensive approach to assessing potential components of cachexia beyond those of weight and sarcopenia.

## CONCLUSIONS

Standardizing the identification of cancer cachexia can improve practice and support targeted interventions. Health systems aiming to implement an algorithm in routine practice should focus on feasibility and ease of use. The Fearon 2011, Cachexia Index, and Evans 2008 algorithms were the most frequently described. While many of the identified algorithms incorporate components for anorexia, appetite, or nutrition; albumin; sarcopenia; and/or weight loss to assess cachexia, the overall literature base included more than 20 different components in a variety of combinations. Patients classified as cachectic had worse survival outcomes. Studies are needed to identify optimal cachexia algorithms and to better understand the relationship between cachexia severity and outcomes such as cachexia progression, function, or quality of life.