# RESULTS

## LITERATURE FLOW AND OVERVIEW

Of 4,546 records screened, 258 were accepted for full-text review. After reviewing these, 114 were eligible for KQ1 and 2, and 49 (a subset of the 114) were eligible for KQ3. The most common reasons for exclusion included not reporting a multicriteria classification algorithm (N = 65) and not being specific to cancer cachexia (N = 29).

## CLASSIFICATION ALGORITHMS TO DIAGNOSE AND STAGE CACHEXIA

For KQ1, 114 studies described 137 (32 unique) cancer cachexia algorithms. These studies were conducted mostly in Europe (N = 36), China (N = 23), and Japan (N = 21); 11 studies were conducted in the US. The included studies were published between 2006 and 2023. Two studies were conducted within the VA. Most studies (N = 99) described algorithms that had a dichotomous definition of cachexia (ie, present or absent), 19 studies described a 3-category definition (eg, no cachexia, mild cachexia, severe cachexia), and 15 studies described a 4-category definition (eg, no cachexia, precachexia, cachexia, refractory cachexia). Four described a continuous risk score. Table 2 shows the 32 different cancer cachexia classification algorithms and their components (see Appendices for full definitions of cachexia algorithms and their components). The Fearon 2011 algorithm, or a modification of it, was the most frequently reported algorithm (N = 68), followed by the Cachexia Index (CXI) (N = 16), the Evans 2008 algorithm (N = 8), and the Glasgow Prognostic Score (GPS) or a modification of it (N = 6). All other classification algorithms were reported in fewer than 5 studies. Eleven studies described an unnamed investigator-developed algorithm. Eight studies, including the 6 that used GPS, described algorithms originally designed to measure other aspects of health, such as malnutrition or inflammation.

Studies described cancer cachexia classification algorithms with a diverse range of components. The individual components included: anorexia, appetite loss, or nutrition measures (N = 18); sarcopenia or skeletal muscle index (SMI) (N = 15); weight loss (N = 15); body mass index (BMI) (N = 15); albumin (N = 14); performance, function, or muscle strength (N = 13); C-reactive protein (CRP) (N = 12); hemoglobin (Hb) (N = 11); white blood cell (WBC) count (N = 4); fatigue (N = 4); neutrophil to lymphocyte ratio (NLR) (N = 3); quality of life (N = 2); dysphagia (N = 1); stomatitis (N = 1); edema (N = 1); ascites (N = 1); serum creatinine (N = 1); or some other component (N = 19), which included: impaired glucose tolerance, diarrhea, nausea, vomiting, abdominal pain, other gastrointestinal symptoms (unspecified), plasma IL-6, plasma pre-albumin, plasma lactate, plasma triglycerides, plasma urea, ROS plasma levels, tumor volume, test/HOMA index altered, absolute lymphocyte number, PG-SGA, GNRI, MUST, MST, SNAQ, NRS-2002, age, cancer site and stage, advanced lung cancer inflammation index, time from symptom onset to hospitalization, platelets, direct bilirubin, dinking (yes/no), total protein, <3 months expected survival, combined or other inflammatory markers (not specified), and underlying chronic disease (not specified). See component details in Appendix for a detailed description of the heterogeneous measures used to evaluate these components. For example, 14 algorithms included physical function measured by the Patient Generated Subjective Global Assessment (PG-SGA), hand grip strength, Karnofsky performance score, Eastern Cooperative Oncology Group (ECOG) scale, or other undefined functional or physical status scores. There were no temporal relationships identified in parameters included in the algorithms; however, several of the more recent algorithms identified developed nomograms as part of their assessment for cachexia. The component details table (see Appendix) also provides a detailed description of the different cutoffs for each measure. For example, weight loss was a component in 15 studies with cutoffs ranging from <2% to >20%.

In summary, 114 studies described 32 unique cancer cachexia algorithms. The most frequently evaluated algorithms included the Fearon 2011 algorithm, the Cachexia Index, and the Evans 2008 algorithm.

Table 2 Components Included in Identified Algorithms

Algorithm | Number of Cachexia Classifications/Stages | Weight Loss | Body Mass Index | Sarcopenia or Skeletal Muscle Index | C-Reactive Protein | Albumin | Neutrophil to Lymphocyte Ratio (NLR) | Anorexia or Appetite Loss or Nutrition | Performance/Function/Muscle Strength^c^ | White Blood Cell Count | Hemoglobin (Hb) | Dysphagia | Stomatitis | Edema | Ascites | Creatinine | Quality of Life | Fatigue | Other | Number of Studies
Fearon 2011 (without modification)^a,b^ | 2 | X | X | X | | | | | | | | | | | | | | | | 53
Fearon 2011 (with modification or staging)^a,b^ | 2-4 | X | X | X | X | | | X | X | | | | | | | | | | X | 15
Cachexia Index (CXI)^a,b^ | Continuous, 2 | | | X | | X | X | | | | | | | | | | | | | 16
Cachexia Staging Score (CSS)^a^ | 3 | X | | X | | X | | X | X | X | X | | | | | | | | | 2
Radiotherapy Cachexia Staging Score (R-CSS) | 3 | X | X | X | | X | | X | X | X | X | | | | | | | | X | 1
Cachexia Assessment Scale (CAS)^b^ | 4 | X | X | | | X | | X | X | | X | X | X | X | X | X | | | X | 1
Evans 2008^a,b^ | 2 | X | X | X | X | X | | X | X | | X | | | | | | | X | X | 8
Cancer Cachexia Score (CCS)^a^ | 3 | | X | X | | | | X | | | | | | | | | | | X | 1
Cancer Cachexia Staging Index (CCSI)^a,b^ | 3 | X | X | X | | X | | X | X | | | | | | | | | | X | 1
Cancer Cachexia Study Group (CCSG)/Fearon 2006^a,b^ | 2 | X | | | X | | | X | | | | | | | | | | | | 4
Cachexia SCOre (CASCO) and miniCASCO^b^ | 3-4 | X | | | X | X | | X | X | | X | | | | | | X | X | X | 3
Glasgow Prognostic Score or modified Glasglow Prognostic Score^a,b^ | 3 or 4 | | | | X | X | | | | | | | | | | | | | | 6
Patient-Generated Subjective Global Assessment (PG-SGA)^b^ | 2 or 3 | | | | | | | | | | | | | | | | | | X | 3
Fearon 2011 and Evans 2008 combined^a^ | 2 - 4 | X | X | X | X | X | | X | X | X | X | | | | | | | | | 4
Hand Grip Strength Cachexia Index (H-CXI)^a,b^ | 2 | | | | | X | X | | X | | | | | | | | | | | 1
Wallengren 2013^a,b^ | 2 | X | | | X | | | | | | | | | | | | | X | | 2
Nutritional Status Algorithm^a^ | 4 | X | X | X | X | X | | X | X | | X | | | | | | | X | X | 1
Orell-Kotikangas 2017^a^ | 2 | | | X | | | | | X | | | | | | | | | | | 1
Solheim 2011 | 3 | | X | | X | | | X | X | | | | | | | | | | | 1
Go 2020^a^ | 2 | | | X | | | | | | | | | | | | | | | X | 1
Namikawa 2022^a^ | 2 | X | X | | X | X | | X | | | X | | | | | | | | | 1
Huo 2022^b^ | Continuous | | | | | | | X | | | | | | | | | X | | X | 1
Liu 2022^b^ | Continuous | | | | | X | | | | | X | | | | | | | | X | 1
Tan 2023^a,b^ | Continuous | | X | X | | | X | X | | | | | | | | | | | X | 1
Yin 2022^b^ | Continuous | | X | | X | | | X | | | X | | | | | | | | X | 1
Vigano 2017^a,b^ | 4 | X | | | X | X | | X | X | X | X | | | | | | | | | 1
Wiegert 2021^a^ | 3 | | X | X | | | | | | | | | | | | | | | | 1
Global Leadership Initiative on Malnutrition (GLIM)^b^ | 2 | X | X | X | | | | X | | | | | | | | | | | X | 1
Malnutrition Universal Screening Tool (MUST)^b^ | 2 | | | | | | | | | | | | | | | | | | X | 1
Nutritional Risk Screening (NRS)-2002^b^ | 2 | | | | | | | | | | | | | | | | | | X | 1
Malnutrition Screening Tool (MST)^b^ | 2 | | | | | | | | | | | | | | | | | | X | 1
Short Nutritional Assessment Questionnaire (SNAQ)^b^ | 2 | | | | | | | | | | | | | | | | | | X | 1
Number of Algorithms Using Each Component | | 15 | 15 | 15 | 12 | 14 | 3 | 18 | 13 | 4 | 11 | 1 | 1 | 1 | 1 | 1 | 2 | 4 | 19 | 137

Notes.

a Included in KQ 3;

b Compared against clinical exam or compared to another cachexia algorithm;

c Measures of muscle strength were included with physical function or performance.

### Fearon 2011 and Its Modifications

Sixty-eight studies described the Fearon 2011 algorithm (N = 53)^7,^ ^16,^ ^38–88^ or some modification of this (N = 15).^8,^ ^89–102^ Both of the studies conducted within the VA used the Fearon 2011 algorithm. The main definition of Fearon 2011 consisted of either weight loss, a combination of weight loss and low BMI, or a combination of weight loss and sarcopenia. Generally, cutoffs for weight loss were ≥5% for weight loss alone and ≥2% when combined with BMI or sarcopenia; although these thresholds and the timing of measurement varied by study (see Appendix). BMI cutoffs included <20 kg/m^2^ and <18.5 kg/m^2^ depending on the study population. Measurements for sarcopenia varied widely and included CT; dual x-ray absorptiometry (DEXA) scan; mid-upper arm mass area (MUAMA); bioelectrical impedance (BIA); strength, assistance walking, rising from a chair, climbing stairs, and falls screening tool (SARC-F); European working group on sarcopenia in older people (EWGSOP) criteria; and other methods. Fifteen studies included modifications (N = 5) or additional staging (N = 10) to the Fearon 2011 algorithm. Additional components used in these studies included CRP measurements (N = 3), appetite, anorexia, or nutritional assessments (N = 4), function, performance, or muscle strength measures (N = 3), impaired glucose tolerance measures (N =1), unresponsiveness to treatment (N = 1), and expected survival estimates (N = 1). Three studies described modifications with 4 stages, 6 studies with 3 stages, and 1 with 2 stages. Stages included no cachexia or normal status, precachexia, cachexia, and refractory cachexia. Weight loss thresholds for modified and staged versions for the Fearon 2011 algorithm ranged from no weight loss for precachexia to ≥15% weight loss for refractory stage cachexia. BMI thresholds for modified or staged Fearon 2011 algorithm ranged from <20 to ≥22 kg/m^2^. Again, definitions of sarcopenia varied across studies (see Appendix).

### Cachexia Index and Its Modifications

Sixteen studies describe the CXI,^49,^ ^80,^ ^103–116^ which was used in most studies to classify patients as either low CXI or stage II (ie, cachectic) or high CXI or stage I (ie, noncachectic). One study classified patients into 3 stages based on SMI using both the L3 vertebral muscles and the pectoralis muscles (PM) at the T4 vertebral level. High CXI had both high L3-CXI and high PM-CXI, intermediate had high L3-CXI and low PM-CXI, and low-CXI groups had low L3-CXI and low PM-CXI, with CXI cutoffs based on the Youden index.^107^ Components for the CXI include measurements of SMI, albumin, and NLR. The CXI was calculated as (SMI × albumin)/NLR, with cutoffs for cachexia varying by sex, measurement of SMI used, and unit of measurement for albumin. Generally, cutoffs were determined by the Youden index or median CXI value for the study sample. One study described a modified version of the CXI that incorporated hand grip strength (H-CXI) as an additional component.^84^ Similar to the original CXI, the H-CXI was calculated as [hand grip strength (kg)/height (m)^2^ × serum albumin (g/L)]/NLR, and cutoffs for cachexia were 175 for males and 113 for females.

### Evans 2008

Eight studies^60,^ ^78,^ ^79,^ ^88,^ ^102,^ ^117’119^ described the Evans 2008 algorithm, which defined cachexia as weight loss or low BMI, plus any 3 of the following: fatigue, anorexia, decreased muscle strength, low fat-free mass index, abnormal serum biochemistry (including increased inflammatory markers, anemia, and low serum albumin).^14^ All 8 studies reported weight loss cutoffs ≥5% over 6-12 months and BMI cutoffs from 18.5-22 kg/m^2^. When specified, sarcopenia was measured using fat-free mass index (measuring low muscle), low muscle mass assessed by appendicular skeletal muscle index or mid-arm muscle circumference, or lean muscle depletion measured by bioelectrical impedance analysis. Decreased muscle strength was measured by hand grip strength, and anorexia was assessed by visual analog scale (VAS), energy intake, or European Organization for Research and Treatment of Cancer (EORTC) questionnaire appetite loss score. Fatigue was measured by the EORTC or VAS. Cutoffs for albumin were <32 g/L or <35 g/L for serum albumin, >5 mg/L for CRP, and Hb cutoffs were <120 g/L or <117 g/L. Other components included unspecified inflammatory markers, IL-6 >4pg/ml, and underlying chronic disease.

### Combined Evans and Fearon

Four studies described a combined Evans 2008 and Fearon 2011 algorithm, which was attributed to Vigano et al.^120–123^ One study included a 2-stage definition of cachexia (eg, yes/no) that was based on weight loss or weight loss and BMI, in conjunction with abnormal laboratory values (CRP, albumin, or Hb)^120^. Two studies included a four-stage definition of cachexia defined as no cachexia, precachexia, cachexia, and refractory cachexia groups, with both subdividing the stage of cachexia as either “cachexia” or “cachexia caused by low BMI or sarcopenia.” The classifications were based on a combination of abnormal laboratory values (CRP, albumin, WBC, or Hb), anorexia or decreased food intake based on the Edmonton Symptom Assessment System (ESAS) or PG-SGA, physical function or muscle strength based on PG-SGA or hand grip strength, and a combination of BMI, weight loss, or sarcopenia measures. A fourth study classified patients into precachexia, cachexia, and refractory cachexia groups, with the refractory cachexia category incorporating the physical function measures.^123^

### Cancer Cachexia Study Group (CCSG)/Fearon 2006

Four studies described the Cancer Cachexia Study Group (CCSG) criteria, which is sometimes called the Fearon 2006 algorithm.^76,^ ^79,^ ^81,^ ^124^ The CCSG classifies patients as cachectic if they meet 2 of the following criteria: CRP ≥10 mg/L, weight loss ≥10%, or caloric intake of ≤1500 kcal/d. One study applied 2 different approaches to classify patients: 1) patients who met 2 criteria and 2) patients who met all 3 criteria.^79^

### Cachexia Score (CASCO) and Mini Cachexia Score (miniCASCO)

Three studies describe the cachexia score (CASCO) and miniCASCO.^61,^ ^125,^ ^126^ The CASCO uses body weight loss and lean body mass; inflammation, metabolic disturbances, fatigue, anemia, immunosuppression; physical performance; anorexia; and quality of life to generate a composite score for cachexia. For the CASCO, 40% of the summary score is based on weight loss or body composition, 20% on inflammatory or metabolic disturbances or immunosuppression, 15% on performance assessed through 5 questions about physical activity, 15% on anorexia assessed by the SNAQ, and 10% on quality of life assessed by the QLQ-C30.^127^ The miniCASCO is an abbreviated version of this tool that uses investigator-developed questions to assess performance, anorexia, and quality of life rather than formal tools, like the SNAQ, and also includes fewer blood components. In the included studies, both the CASCO and miniCASCO used a numeric scale from 0-100 to classify patients into 4 groups: no cachexia (≤14), mild (15–28), moderate (29–46), and severe (>46) cachexia. However, 1 identified study used the CASCO to classify patients into 3 cachexia groups: no cachexia, precachexia, and cachexia without specifying any scoring system.

### Cachexia Staging Score and Radiotherapy Cachexia Staging Score

Three studies used either the Cachexia Staging Score (CSS) or the Radiotherapy Cachexia Staging Score (R-CSS), a modification of the CSS.^13,^ ^128,^ ^129^ The CSS assigns points to measurements of weight loss, strength, assistance with walking, rising from a chair, climbing stairs, and falls (SARC-F) questionnaire score, Eastern Cooperative Oncology Group Performance Status (ECOG-PS) score, appetite loss, and abnormal biochemistry, defined as WBC count >10 × 10^9^/L, albumin <35 g/L, and Hb of <120 g/L for males and 110 g/L for females. Total CSS score ranges from 0-12, which is used to classify patients as noncachectic (0-2), precachexia (3-4), cachexia (5-8), or refractory cachexia (9-12). The R-CSS added 3 additional components for age, BMI, and food intake. The total score for the R-CSS ranges 0-17 with scores of 0-3 indicating no cachexia, 4-6 indicating precachexia, 7-12 indicating cachexia, and 13-17 indicating refractory cachexia.

### Cancer Cachexia Staging Index

One study described the Cancer Cachexia Staging Index (CCSI).^130^ The CCSI assigns point values to subjective and objective measures. Subjective measures include BMI adjusted weight loss grade with cutoffs of 0, 1, 2, 3, and 4, weight loss rates with cutoffs of 0.38 and 1.7 kg/month, inflammation defined by a combination of NLR (cutoff of 3.5) and CRP levels (cutoffs of 2.9 or 2.3mg/L), prealbumin with a cutoff of 180 mg/L, and skeletal muscle index with cutoffs of 44.4 and 35.7 cm^2^/m^2^ in males and 37.5 and 30.9 cm^2^/m^2^ in females. Objective measures include appetite and physical status, both assessed as good, fair, or poor. Total scores range from 0-27 with scores <9 defined as no cachexia, score of 9-18 indicating mild or moderate cachexia, and those ≥19 indicating severe cachexia.

### Wallengren 2013 Algorithm

Two studies described the Wallengren 2013 algorithm.^79,^ ^123^ This algorithm used weight loss, fatigue, and CRP to categorize patients as cachectic or noncachectic based on cutoff values of >2% for weight loss, >3 for fatigue score on a visual analog scale of 1–10 or the ESAS, and CRP >10 mg/L for CRP.

### Nomograms to Identify Cachexia

Four studies described nomograms to classify patients as cachectic.^53,^ ^58,^ ^75,^ ^85^ The Liu 2022 nomogram was specific to lung cancer patients and included components for cancer stage, albumin, anemia, advanced lung cancer inflammation index, and surgery. The nomogram developed by Huo 2022 included age, nutritional risk screening (NRS 2002), PG-SGA, quality of life (EORTC QLQ–C30), and cancer category (based on site of primary cancer). The nomogram developed by Tan 2023 included cancer site, cancer stage, time from symptom onset to hospitalization, appetite loss (not defined), BMI, SMI [skeletal muscle area (cm^2^)/height (m^2^)], and NLR. The nomogram by Yin 2022 included BMI, cancer type, anorexia, platelet count, early satiety, abdominal pain, diarrhea, vomiting, CRP, other gastrointestinal symptoms, Hb, direct bilirubin, drinking status, tumor stage, and total protein. Each nomogram utilized the indicated algorithm to calculate a composite score that was associated with cachexia risk.

### Cachexia Assessment Scale

One study described the Cachexia Assessment Scale (CAS).^131^ The CAS assigns points to investigator-developed assessment questions about functional status, weight loss, BMI, stomatitis, edema, ascites, albumin, Hb, serum creatinine, dysphagia, loss of appetite, diarrhea, nausea, and vomiting. For each component, a score of 0-4 is assigned, with lower scores indicating better outcomes. If 0-1 components receive a score of 1-2 and no components receive a score of 3-4, patients are classified as not cachectic. A combination of 2 or more components receiving a score of 1-2 and 0 receiving a score of 3-4 corresponds with mild cachexia, a combination of 2 or more components receiving a score of 1-2 and 1-2 receiving a score of 3-4 corresponds with moderate cachexia, and any components receiving a score of 1-2 with 3 or more receiving a score of 3-4 corresponds with severe cachexia.

### Nutritional Instruments Adapted to Classify Cachexia

Eleven studies described the application of instruments originally developed to identify other symptoms/disease (eg, malnutrition and nutritional status) to identify cachexia. It is important to consider that these instruments were originally developed with the intended purpose of identifying conditions related to cachexia and may therefore present challenges in distinguishing between cachexia and the original condition of interest.

Six studies described the Glasgow Prognostic Score (GPS), which was also referred to as the modified Glasgow Prognostic Score (mGPS).^91,^ ^132–136^ GPS uses a combination of albumin and CRP to determine a summary score (0 to 2). The CRP cutoffs were 5 and 10 mg/dL, and all 6 studies used the same cutoff for albumin (35 g/L). Four studies used a 4-stage definition which consisted of no cachexia/normal (CRP<10 mg/L, ≤10 mg/L, or ≤0.5 mg/L and albumin ≥35 g/L; score = 0), undernourished (CRP≤10 mg/L, <10 mg/L, or ≤5mg/L and albumin <35 g/L; score = 0), precachexia (CRP>10 mg/L, ≥10mg/L, or >5 mg/L and albumin ≥35 g/L; score = 1), and cachexia or refractory cachexia (CRP>10 mg/L or ≥10 mg/L and albumin <35 g/L; score = 2. One study classified patients as either cachectic or not (score of 2 equated to cachexia^135^), and another study used a 3-stage definition of cachexia including no cachexia (0 component met), precachexia (1 component met), and cachexia (2 components met).

One study described a nutrition status (NS) algorithm.^137^ The NS uses a combination of handgrip strength (cutoff of 30 kg), fat-free mass index (cutoff of 14.6 kg/m^2^), fatigue, appetite loss, weight loss (cutoff of 5% over 12 months), BMI (cutoff of 20 kg/m^2^), CRP (5 mg/L cutoff), Hb (120 g/L cutoff), albumin (32g/L cutoff), and the PG-SGA (cutoff score of 4). Based on these measures, patients were classified as having cachexia, sarcopenia, nutritional risk without sarcopenia or cachexia, or well nourished. Those with handgrip strength or fat-free mass index below the cutoff and at least 2 of the following were classified as cachectic: fatigue, appetite loss, weight loss or BMI, and abnormal blood chemistry. Those who did not meet handgrip or free-fat mas index criteria but had 3 of these components were also classified as cachectic.

Three studies reported on the PG-SGA to identify cachexia.^69,^ ^92,^ ^118^ The PG-SGA was originally developed to assess nutritional status using patient-reported weight, symptoms, food intake, activities and function. Each component is scored. Total scores ranged from 0-52. Scores ≥ 9 indicated need for nutritional intervention.^138,^ ^139^

One study used the Global Leadership Initiative on Malnutrition (GLIM) as a tool to identify cachexia, with and without nutritional risk screening using the nutritional risk screening 2002 (NRS-2002).^69^ The GLIM was originally developed to assess malnutrition, using measures of weight loss, low BMI, reduced muscle mass, and disease burden. The GLIM was used with and without nutrition risk screening to assess cachexia.

One study used 4 different malnutrition tools to identify cachexia: the malnutrition universal screening tool (MUST), NRS-2002, malnutrition screening tool (MST), and the short nutritional assessment questionnaire (SNAQ)^16^. Cutoffs tested for cachexia identification were ≥1 for the MUST, ≥3 for the NRS-2002, ≥2 for the MST, and ≥2 for the SNAQ.

### Other Investigator-Developed Cachexia Assessments

Seven studies reported other investigator-identified algorithms for assessing cachexia. One study described a 4-stage definition, 3 studies described a 3-stage definition, and 3 studies described a 2-stage definition.

Vigano 2017 used a combination of abnormal biochemistry (CRP >10mg/L, WBC >11,000/L, albumin <32 g/L, or Hb <120 g/L in men and <110 g/L in women), decreased food intake (aPG-SGA), moderate or significant weight loss (5% cutoff), and decreased activities and functioning (aPG-SGA) to classify patients into 4 stages (noncachexia, precachexia, cachexia, and refractory cachexia) depending on the combination of criteria met.

Solheim 2011 used BMI (20 kg/m^-2^ cutoff), Karnofsky score (<80), CRP (≥10 mg1^-1^), and appetite loss (EORTC QLQ-C30) to classify patients into 3 stages: no cachexia (less than 2 components), mild cachexia (2-3 components), or severe cachexia (all 4 components). One study described the Cancer Cachexia Score (CCS). The CCS assigns point values of 0 or 1 to sarcopenia (yes/no), BMI (cutoff 20kg/m^2^), prognostic nutritional index (cutoff of 40), and tumor volume (size by T-stage, with a cutoff of 57.5). Three cachexia stages are defined as mild (score of 0-1), moderate (2), and severe (3-4).^115^ Wiegert 2021 used a combination of BMI (cutoffs of 21.0 to 26.4), mid-upper-arm muscle area (cutoffs of 38.0 cm^2^ for men and 35.5 cm^2^ for women), and weight loss (15.0% cutoff) to classify patients into 3 stages (precachexia, cachexia, or refractory cachexia) depending on the combination of criteria met.

Orell-Kotikangas 2017 used the combined definition of low muscle mass (mid-arm muscle area <10^th^ percentile) and low muscle function (hand grip strength <85% normal median value) to categorize patients into 2 stages (cachectic and noncachectic). Of note, this definition included components more closely related to assessing sarcopenia. Go 2020 used a combination of sarcopenia (measured by L3-SMI or PM-SMI) and the geriatric nutritional risk index (GNRI) into 2 stages (high cachexia risk and low cachexia risk). Patients considered to be at high risk for cachexia were those with major GRNI risk, sarcopenia using both L3-SMI and PM-SMI, or moderate GNRI risk plus sarcopenia using 1 measure; otherwise, patients were flagged as low risk of cachexia. Namikawa 2022 classified patients into 2 stages (cachectic and noncachectic) based on either a) weight loss (5%) or weight loss (2%) and BMI (<20 kg/m^2^); b) anorexia (not defined); or c) 2 or more of the following: albumin <32 g/L, CRP >5.0 mg/L, and Hb <12 g/dL.

## PERFORMANCE CHARACTERISTICS OF ALGORITHMS

Twenty-two of the 32 identified algorithms were compared to either clinical exam or to another cachexia algorithm. In terms of performance characteristics, the Fearon 2011 algorithm was frequently used as a comparator for other cachexia assessments (see Appendix). No study evaluated the performance characteristics of Cachexia Staging Score or Radiotherapy Cachexia Staging Score, Cancer Cachexia Score, nutritional status algorithm, the algorithms developed by Orell-Kotikangas 2017, Solheim 2011, Go 2020, Namikawa 2022, Wiegert 2021, or the combined use of the Fearon 2011 and Evans 2008 algorithms. Among algorithms that were compared to either clinical exam or to another cachexia algorithm performance, there is no obvious best choice.

### Fearon 2011 and Its Modifications

One study found only slight agreement, defined by the study as a Kappa of 0.00–0.20, between the Fearon 2011 algorithm and a clinical assessment of cachexia based on oncologists’ opinion (Kappa 0.049, 95% CI [–0.079, 0.176], p = 0.457).^77^

### Cachexia Index and Its Modifications

Three NRCS compared the CXI or H-CXI to the Fearon 2011 algorithm.^49,^ ^84,^ ^130^ One study found that significantly more patients were classified as cachectic (according to Fearon 2011) in the low-CXI compared to the high-CXI group (35% vs 22%, p = 0.01).^80^ The other NRCS found no significant difference in the proportion of patients classified as cachectic (according to Fearon 2011) in the low-CXI versus high-CXI groups (50.9% vs 41.6%, p = 0.09).^49^ Finally, 1 study found a greater proportion of patients in the low H-CXI group were classified as cachectic using the Fearon 2011algorithm compared to the high-H-CXI group (31.0% vs 17.6%; p NR). The same study found a low H-CXI was independently associated with risk of developing cancer cachexia as defined by the Fearon 2011 algorithm in the multivariable analysis.^84^

### Evans 2008

Three NRCS compared the Evans 2008 to the Fearon 2011 algorithm.^78,^ ^88,^ ^102^ Two studies found more patients were classified as cachectic using the Evans compared to the Fearon (27.5% vs 17.5%, p NR). In this study, 31.0% of patients classified as noncachectic by the Evans 2008 algorithm were classified as precachexia by the Fearon algorithm.^102^ Another study found that 45.5% of patients with cancer were classified as cachectic using the Evans 2008 algorithm compared to 39.4% using the Fearon 2011 algorithm (p NR).^88^ One other NRCS reported fewer patients were classified as cachectic according to the Evans 2008 algorithm compared to Fearon 2011 (40% vs 70%, p NR).^78^

### Modified Glasgow Prognostic Score

Two studies compared the mGPS to the Fearon 2011 algorithm. One study found that fewer patients were classified as cachectic using the mGPS compared to Fearon 2011 criteria (60% no cachexia, 5% undernourished, 25% precachectic, and 10% refractory cachexia vs 40% noncachectic, 5% precachectic, and 55% cachectic), but these differences were not significant (McNemar’s test p = 0.43).^91^ Another study found that patients identified as cachectic using the Fearon 2011 criteria had greater odds of being classified as having refractory cachexia (OR = 2.83, [1.73, 4.60]) or undernourished (OR = 1.84, [1.23, 2.75]) in the mGPS.^136^

### PG-SGA

Three studies compared the PG-SGA to Evans 2008. One NRCS compared the PG-SGA with a cutoff of 6.5 to the Evans 2008 algorithm (sensitivity = 79.8%, specificity = 72.3%, and AUC of 0.846).^118^ Another NRCS compared the PG-SGA to the Fearon 2011 algorithm (sensitivity = 86.2%, specificity = 58.3%, and AUC = 0.778).^69^ A third NRCS reported a positive correlation between PG-SGA score and the categories of cachexia proposed by Fearon (r = 0.54; p < 0.0001).^92^

### Wallengren 2013

Two studies compared the Wallengren 2013 algorithm to a reference algorithm. One NRCS found that more patients were classified as cachectic according to the Wallengren algorithm (37%) compared to the Fearon 2006 algorithm (12% based on all 3 components of the Fearon 2006 algorithm and 45% based on 2 of 3 of these components) and the Evans 2008 algorithm (33%). The same study found that fewer patients were classified as cachectic according to the Wallengren algorithm compared to the Fearon 2011 algorithm (37% vs 85%, p NR).^79^ Another NRCS found fewer patients were classified as cachectic according to Wallengren algorithm (13.8%) compared to the Vigano 2017 algorithm (8.2% not cachectic, 20.8% were precachectic, 17.3% cachectic, and 53.3% refractory cachexia).^123^

### Nomograms

All 4 identified nomograms were compared against the Fearon 2011 algorithm. Liu 2022 reported AUCs of 0.702 for the training set and 0.688 for the validation set.^58^ Huo 2022 reported a sensitivity of 0.826, specificity of 0.862, and AUC of 0.925 in the development cohort and 0.854, 0.829, and 0.923 (p NR) in the validation cohort.^53^ Tan 2023 reported an AUC of 0.751 (95% CI [0.725, 0.777], p < 0.001) in the application cohort, indicating that this tool can identify those with and without cachexia.^75^ Yin 2022 reported an accuracy of 0.714, kappa of 0.396, sensitivity of 0.580, specificity of 0.808, positive predictive value of 0.679, and negative predictive value of 0.733 for on the final model used to create the nomogram.^85^

### Other Algorithms

One NRCS compared the CCSG/Fearon 2006 algorithm to the Fearon 2011, and found both algorithms classified a similar proportion of patients as cachectic (64% vs 60%, McNamar’s test p = 0.75).^81^

One NRCS reported a moderate correlation between CASCO and subjective cachexia diagnoses from specialized oncologists (ρ = 0.412, p < 0.001). The same study reported a strong correlation between the CASCO and miniCASCO (r = 0.964, p < 0.001.)^125^

Using the Fearon 2011 algorithm as the reference determination of cachexia, the CCSI had an area under the receiver operating characteristics curve (AUC) to evaluate test accuracy of 0.911.^130^

One NRCS compared the GLIM to the Fearon 2011 algorithm. The GLIM had a sensitivity of 100%, specificity of 60.7%, accuracy of 67.4%, and AUC of 0.835. When nutritional risk screening (NRS-2002) was added, the GLIM had a sensitivity of 88.8%, specificity of 91.8%, accuracy of 91.3%, and AUC of 0.910.^69^

One study compared the MUST, NRS-2002, MST, and SNAQ to the Fearon 2011 definition of cachexia.^16^ For 3 instruments, sensitivity was between 76.6% and 87.3% and in 1 instrument (SNAQ) sensitivity was 54.3%. For all 4 instruments, specificity was between 77.7% and 98.6%, accuracy was between 80.9% and 93.5%, and AUC was between 0.751 and 0.914.

One NRCS found a significant correlation between the CAS and PG-SGA (r = 0.58, p = 0.04). However, it was not clear if the PG-SGA was used by the authors to define cachexia or malnutrition.^131^

## OUTCOMES FOR PATIENTS FOLLOWING CACHEXIA CLASSIFICATION

Forty-nine studies reported the adjusted association between cachexia as determined with a described algorithm and a prioritized outcome. The majority of studies were from Japan (N = 13), China (N = 9), and Korea (N = 5), with 3 conducted in the US. The studies were conducted between 1991 and 2002 and with a wide range of follow-up durations (10 days to 12 years). A total of 31,317 patients were included. The mean age of patients in 24 studies ranged from 57.8 to 75.6 years; the median age in 22 studies was between 57 and 83 years. In 2 studies, the majority of patients were ≤65 years old, and 1 study reported that the majority of patients were ≥60 years old. Males made up 40.5% to 100% of patients. Only 3 studies reported information on patient race/ethnicity, with White patients making up less than half of all participants in these studies (34.4-48%), Black patients making up 52% and 16.5% of samples in 2 of these studies, and 1 study reporting 40.5% of patients of “other” race. The studies included patients with a variety of cancers, including cancers of the head and neck; gastrointestinal tract; lung; breast; prostate; pancreas; skin, bones, and soft tissue; gynecological; genitourinary; and others, with patients with more advanced stages making up the majority of patients included. See the Appendix for further details on cancer treatments and patient comorbidities in each study. Overall survival was the most commonly reported outcome (reported on 50 times in 44 studies) followed by progression-free survival (N = 11), disease-free survival (N = 8), and relapse-free survival (N = 2). Other outcomes included function (N = 2), hospitalization (N = 2), or cachexia relevant burden or severity (N = 2). No study evaluated cachexia progression or feeding tube placement.

Two studies used propensity score matching to adjust for confounding and had no other concerns (therefore both low risk of bias). The remaining 47 studies used multivariable regression to adjust for confounding. Forty studies had moderate risk of bias due to concerns over attrition bias due to large loss to follow-up, lack of clear reporting or clear eligibility criteria, or because of analysis used for adjustment. Seven studies had high risk of bias. Six of these either adjusted for multiple cachexia algorithms in the same model, or adjusted for variables that were also included components of the cachexia algorithm. The seventh study had concerns surrounding high loss to follow-up, unclear reporting or eligibility criteria, and adjustment method used.

Overall, regardless of classification algorithm, overall survival, cancer progression-free survival, and disease-free survival were worse for patients with cancer cachexia. Those with cancer cachexia also had worse relapse-free survival, worse symptom burden, and longer hospital length of stay. Results in functional outcomes were inconsistent. No study reported feeding tube placement or cachexia progression outcomes.

### Fearon 2011 Algorithm

In summary (Table 3), patients identified as cachectic using the Fearon 2011 algorithm had worse overall mortality (moderate confidence), progression-free survival (moderate confidence), and disease-free survival (low confidence) when compared to noncachectic patients. Cachectic patients also had greater hospital and ICU length of stay (low confidence) and greater perception of dysphagia (low confidence). No studies used the Fearon 2011 algorithm to assess function outcomes, cachexia progression, or feeding tube placement.

#### Overall Survival

Fifteen studies reported overall survival for patients with and without cachexia based on the Fearon 2011 algorithm or some modification of this algorithm. Two studies were excluded from meta-analysis. One NRCS classified patients by the number of Fearon 2011 algorithm criteria met (see Appendix).^65^ The NRCS found worse mortality for patients who met all 3 Fearon 2011 criteria compared to those who only met 1 or 2 of the criteria (HR = 1.40, 95% CI [1.078, 1.819]). Another NRCS used a modified version of the Fearon 2011, and thus was excluded from the meta-analysis, but found a similar association (HR = 2.93, 95 % CI [1.03, 8.34]). They also found an imprecise estimate of survival difference between precachectic and noncachectic patients (HR = 0.78, 95 % CI [0.30, 2.03]).^102^

Thirteen NRCSs found a significantly worse mortality among people with cachexia (pooled HR= 1.59, 95% CI [1.36, 1.86]; Figure 1). Only 1 study found a lower hazard of dying among those with cachexia, but the estimate was non-significant with a wide confidence interval.^61^ Notably, this study controlled for multiple definitions of cachexia within the same models, raising concerns of collinearity.^49^

Figure 1 Overall Survival for Fearon 2011

Abbreviations. Est=estimated based on KM curve; F/u=follow-up; HR=hazard ratio; Med=Median; mo=month; N=sample size; NR=not reported; OS=overall survival; RoB=risk of bias.

#### Cancer Progression-Free Survival

Four NRCSs reported cancer progression-free survival for people classified with and without cachexia following the Fearon 2011 algorithm. Pooled data from 4 studies found significantly worse cancer progression-free survival for people with versus without cachexia (pooled HR = 2.05, 95% CI [1.40, 3.02]; Figure 2).

Figure 2 Progression-Free Survival for Fearon 2011

Abbreviations. F/u=follow-up; HR=hazard ratio; Med=median; mo=month; N=sample size; PFS=progression-free survival; RoB=risk of bias.

#### Disease-Free Survival

One NRCS found worse disease-free survival among people classified as cachectic using the Fearon 2011 algorithm (HR= 1.53, 95% CI [1.21, 1.94]).^87^

#### Hospital Length-of-Stay-Related Outcomes

Two NRCSs reported hospital length of stay for people with and without cachexia using the Fearon 2011 algorithm. One NRCS found a significantly longer postoperative length of stay for patients with cachexia compared to their noncachectic counterparts (β = 2.41 days, 95% CI [0.28, 4.55]).^48^ Another NRCS found a significantly longer median hospital stay for patients classified as cachectic than their noncachectic counterparts matched on propensity score (10.0 vs 7.0 days, p < 0.001).^54^ The same study also reported cachectic patients had significantly longer intensive care unit (ICU) stays (median [IQR] 2.0 [2–3] vs 2.0 [2–2], p < 0.001), and cachectic patients had a greater risk for having an ICU stay >48 hours compared to patients without cachexia (RR [95% CI] = 2.06 [1.40, 3.04]). A prospective study found a greater risk of a score of 3 or more on the EAT-10 among those with cachexia (HR = 9.00, 95% CI [2.48, 32.62]), which indicated a greater perception of oropharyngeal dysphagia.^83^

Table 3 Summary of Findings for Fearon 2011^a^

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary^a^ | Overall Confidence
Overall Survival | 15 (4,924); NRCS, Validation^43,^ ^44,^ ^51,^ ^52,^ ^61,^ ^63–65,^ ^68,^ ^76,^ ^78,^ ^87,^ ^88,^ ^102,^ ^118^ | Moderate^b^ | Direct | Precise | Consistent | None | Fearon: sumHR 1.59 (1.36, 1.86); Mod Fearon: HR 2.93 (1.03, 8.34)^c^; 3 vs 1-2 criteria: HR 1.40 (1.08, 1.82)^c^ | Moderate
Progression-Free Survival | 4 (576); NRCS^51,^ ^52,^ ^64,^ ^77^ | Moderate^d^ | Direct | Precise | Consistent | None | SumHR 2.05 (1.40, 3.02) | Moderate
Disease-Free survival | 1 (1215); NRCS^87^ | Moderate^d^ | Direct | Precise | Consistent | Single Study | HR 1.53 (1.21, 1.94) | Low
Hospitalizations | 2 (350); NRCS^48,^ ^54^ | Moderate^e^ | Direct | Imprecise^f^ | Consistent | N/A | Overall LOS and ICU day significantly longer in those with cachexia compared to no cachexia. Greater risk of prolonged IUC stay (RR = 2.06 [1.40, 3.04]) | Low
Cachexia Symptom Burden | 1 (66); NRCS^83,^ ^140^ | Moderate^d^ | Direct | Precise | Consistent | Single Study | EAT-10 ≥3 HR = 9.00 (2.48, 32.62) | Low
Cachexia Progression | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Function | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Feeding Tube Placement | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence

Notes.

a HR estimates >1 indicate worse outcome (eg, higher likelihood of death);

b Three studies were rated as high risk of bias and 12 were rated as moderate risk of bias;

c One study;

d All included studies were rated as having moderate risk of bias;

e One study was rated as low risk of bias and 1 was rated as moderate risk of bias;

f Imprecise estimate for postoperative length of stay.

Abbreviations. EAT-10=eating assessment tool; HR=hazard ratio; ICU=intensive care unit; IQR=interquartile range; LOS=length of stay; N/A=not applicable; NRCS=nonrandomized comparative study; RR=relative risk; sumHR=summary (or pooled) hazard ratio.

### Cachexia Index

In summary (Table 4), using the CXI, people identified as cachectic, having low CXI, or stage II cachexia had worse overall mortality (low confidence), progression-free survival (moderate confidence), disease-free survival (moderate confidence), or relapse-free survival (low confidence) compared to those who were not. No studies used the CXI to assess cachexia symptom burden, functional levels, hospitalization outcomes, cachexia progression, or feeding tube placement.

#### Overall Survival

Sixteen studies evaluated overall survival based on the Cachexia Index (CXI) or a modification of this algorithm. Studies applied unique cutoffs (eg, based on population specific Youden’s index values or based on median values) to classify patients as low CXI or high CXI. One study used median CXI values to classify patients as stage I cachexia and stage II cachexia, with those in stage II having a lower CXI.^110^ The majority of these studies used the CXI as a biomarker for cachexia and its prognosis, but only 2 studies explicitly labeled the low-CXI group as “cachectic” and the high-CXI group as “noncachectic.” One study used a modified version of the CXI that included hand grip strength and, thus, was excluded from the pooled analysis. This study reported greater mortality in patients with low H-CXI group versus high H-CXI (HR = 1.61, 95% CI[1.45, 1.79]).^84^ The pooled data from 15 studies found a significantly worse overall mortality for patients with low CXI compared to high CXI (pooled HR = 2.32, 95% CI [1.98, 2.71]; Figure 3).

Figure 3 Overall Survival

Notes. CXI indicates cachexia or cachexia risk. (1) Estimate from Go 2021 (PMID 34001060) for patients with limited-stage disease; (2) Estimate from Go 2021 (PMID 34001060) for patients with extensive-stage disease; (3) Estimate from PMID 34676685; (4) 95% CI calculated from reported p-value.

Abbreviations. Est=estimated based on KM curve; F/u=follow-up; H=high CXI; HR=hazard ratio; L=low CXI; Med=median; mo=month; N=sample size; OS=overall survival; RoB=risk of bias.

One NRCS found no significant difference in overall survival between patients classified as intermediate-CXI compared to high CXI (HR =1.72, 95% CI [0.99, 2.97]).^107^ This was the only study to use the intermediate-CXI classification. While the results of the intermediate versus high-CXI groups were excluded from the meta-analysis, this study also compared low-CXI versus high-CXI groups, the results of which were included in the meta-analysis. Importantly, 1 NRCS conducted a propensity score match analysis and multivariable regression. The propensity score match analysis but not multivariable regression analysis found a significantly worse mortality for those in the low-CXI group (p = 0.041 and p = 0.940, respectively).^103^

#### Cancer Progression-Free Survival

Five NRCSs found a significantly worse progression-free survival for patients classified as low CXI (pooled HR = 1.91, 95% CI [ 1.57, 2.33]; Figure 4).

Figure 4 Progression-Free Survival

Notes. Go 2021 (1) = Patients with limited-stage small cell lung cancer from PMID 34001060; Go 2021 (2) = Patients with extensive-stage small cell lung cancer from PMID 34001060; Go 2021 (3) = patients with diffuse large B-cell lymphoma from PMID 34676685.

Abbreviations. Est=estimated based on KM curve; F/u=follow-up; HR=hazard ratio; Med=median; mo=month; N=sample size; PFS=progression-free survival; RoB=risk of bias.

#### Disease-Free Survival

Pooled data from 5 studies showed significantly worse disease-free survival for patients classified low CXI (pooled HR = 1.89, 95% CI [1.46, 2.44]; Figure 5).

Figure 5 Disease-Free Survival

Abbreviations. CXI=cancer cachexia index; DFS=disease-free survival; F/u=follow-up; HR=hazard ratio; Med=median; mo=month; N=sample size; RoB=risk of bias.

#### Relapse-Free Survival

One study reported significantly worse relapse-free survival for those classified as low CXI compared to high CXI (HR = 1.58, 95% CI [1.06, 2.34]).^141^

Table 4 Summary of Findings for Cachexia Index^a^

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Overall Survival | 16 (8,191); NRCS; Validation^49,^ ^80,^ ^84,^ ^103,^ ^104,^ ^106–114,^ ^116,^ ^141^ | Moderate^b^ | Indirect^c^ | Precise | Consistent | | Pooled HR = 2.32 (1.98, 2.71); Modified CXI^a^ HR = 1.61 (1.45, 1.79) | Low
Progression-Free Survival | 5 (847); NRCS^106–108,^ ^110,^ ^112^ | Moderate^d^ | Direct | Precise | Consistent | | Pooled HR = 1.91 (1.57, 2.33) | Moderate
Disease-Free Survival | 5 (936); NRCS^103,^ ^109,^ ^111,^ ^113,^ ^116^ | Moderate^e^ | Direct | Precise | Consistent | | Pooled HR = 1.89 (1.46, 2.44) | Moderate
Relapse-Free Survival | 1 (239); NRCS^141^ | Moderate^f^ | Direct | Precise | Consistent | Single study | HR = 1.58 (1.06, 2.34) | Low
Function | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Hospitalizations | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Cachexia Progression | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Cachexia Symptom Burden | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Feeding Tube Placement | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence

Notes.

a One study used a modified version of the CXI;

b Three studies were rated as high risk of bias, 1 was rated as low risk, and 12 were rated as moderate risk;

c Studies used different cutoff values to distinguish low versus high groups;

d All studies were rated as moderate;

e One study was rated as high risk of bias, 1 study was rated as low, and 3 were rated as moderate risk of bias;

f Study was rated as moderate risk due to use of multivariable regression for adjustment.

### Evans 2008 Algorithm

In summary (Table 5), 4 studies compared overall survival by cachexia based on the Evans 2008 algorithm. Pooled data showed significantly worse overall survival among those classified as cachectic (pooled HR = 4.24, 95% CI [2.60, 6.90]; Figure 6). No studies used the Evans 2008 algorithm to assess cachexia symptom burden, functional levels, hospitalization outcomes, cachexia progression, and feeding tube placement.

Figure 6 Overall Survival for Evans 2008

Notes. (1) = Comparison in this study was between patients with sustained cachexia both before and after treatment versus patients without cachexia at all time periods.

Abbreviations. Est=Estimated based on KM curve; F/u=follow-up; HR=hazard ratio; Med=median; mo=month; N=sample size; OS=overall survival; RoB=risk of bias.

Table 5 Summary of Findings for Evans 2008

Outcome | Studies (Patients); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | HR (95% CI) | Quality
Overall Survival | 4 (668); NRCS^78,^ ^88,^ ^102,^ ^119^ | Moderate^a^ | Direct | Precise | Consistent | | Pooled HR = 4.24 (2.60, 6.90) | Moderate
Function | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Hospitalizations | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Cachexia Progression | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Cachexia Symptom Burden | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence
Feeding Tube Placement | 0 | N/A | N/A | N/A | N/A | N/A | N/A | No evidence

Notes.

a All studies rated as moderate risk of bias.

### Fearon 2006

Two studies used the Fearon 2006 algorithm (see Appendix), which included weight loss, CRP, and energy intake components and found worse mortality for people classified with cachexia. One study reported significantly worse overall survival among those classified as cachectic compared to their counterparts without cachexia (HR = 2.26, 95% CI [1.18, 4.32]).^76^ Another study found significantly worse 6 month mortality rates among patients who met 2 of 3 of the Fearon 2006 criteria or all 3 criteria compared to people who did not meet any criteria (HR = 2.23, p < 0.001 and HR = 2.96, p < 0.001). The same study found worse mortality rates among patients with stage II or III cancer who met 2 of 3 and all 3 Fearon 2006 compared to people not meeting any criteria (HR = 2.40, p < 0.001 and 4.94, p < 0.001). However, there were no significant differences in mortality in patients with stage IV cancer who met 2 of 3 or all 3 Fearon 2006 compared to people not meeting any criteria (HR = not reported).^124^ No studies used the Fearon 2006 algorithm to assess cachexia symptom burden, functional levels, hospitalization outcomes, cachexia progression, or feeding tube placement.

### Glasgow Prognostic Score

Two studies used the GPS to classify patients as cachectic (see Appendix). One study found significantly worse overall survival among patients classified as precachectic or with refractory cachexia compared to no cachexia (HR = 2.00, 95% CI [1.34, 2.98] and HR = 2.45, 95% CI [1.34, 2.98]).^136^ The same study also reported no significant difference in hyporexia between those with precachexia and no cachexia, but people with refractory cachexia had greater odds of hyporexia (OR = 3.20, 95% CI [2.25, 4.55]), nausea (OR = 2.13, 95% CI [1.52, 2.99]), intestinal constipation (OR = 1.75, 95% CI [1.26, 2.44]), xerostomia (OR = 2.00, 95% CI [1.43, 2.80]), dysgeusia (OR = 1.89, 95% CI [(1.36, 2.63]), and fatigue (OR = 1.06, 95% CI [0.53, 1.59]). Another study found those classified as noncachectic (GPS) had greater odds of stable or improved Karnofsky performance status outcomes compared to those classified as having refractory cachexia (OR = 1.95 [1.01, 3.47]). In the same study, quality of life measured by improved or stable (vs not) Karnofsky performance status appeared to differ between patients classified as cachectic and those with refractory cachexia (OR = 0.45, 95% CI [0.29, 1.03]), but this difference was not significant.^132^ No studies used the GPS to assess hospitalization outcomes, cachexia progression, or feeding tube placement.

### Other Assessments

Eleven other studies applying 12 different algorithms to classify patients as cachectic reported on overall (N = 11),^75,^ ^115,^ ^120,^ ^123,^ ^128,^ ^130,^ ^137,^ ^142–145^ progression-free (N = 2),^120,^ ^142^ disease-free (N = 2),^115,^ ^144^ relapse-free survival (N = 1),^75^ or function (N = 1)^137^(see Appendix).

Nine of 11 studies found significantly worse overall survival (range in HR = 1.34 to 11.0) for people classified as cachectic compared to those without cachexia, or to those with more severe cachexia. One study reported worse overall survival for people classified to the severe cachexia group compared to those with moderate or mild cachexia by the Cancer Cachexia Score (HR = 2.94, 95% CI [1.81, 4.75]).^115^ In a sample of people with cancer who were receiving support from a palliative care team, 1 study used the Cachexia Staging Score and reported worse overall survival in patients with precachexia (HR = 2.78, 95% CI [0.62, 12.46]), cachexia (HR = 4.77, 95% CI [1.09, 20.80]), and refractory cachexia (HR = 11.00, 95% CI [2.37, 51.07]) compared to those without cachexia.^128^ Another study used the Cachexia Staging System in palliative care patients and reported worse overall survival among those with cachexia (HR = 1.35, 95% CI [1.12, 1.99]) and refractory cachexia (HR = 1.84, 95% CI [1.21, 2.79]) compared to those with precachexia.^145^ A study of patients with cancers of various sites used the Cancer Cachexia Staging Index to identify patients with mild, moderate, or severe cachexia. The study reported worse overall survival for people with mild or moderate cachexia (HR = 2.17, 95% CI [1.64, 2.88]) or severe cachexia (HR = 3.99 (2.45, 6.49) compared to people without cachexia.^130^ One study of palliative care patients with cancer reported worse overall survival in people identified as cachectic using the algorithm developed by Wallengren (HR = 2.21, 95% CI [1.86, 2.62]) compared to those who did not.^123^ The same study also used an algorithm developed by Vigano and found worse survival in patients with precachexia (HR = 1.87, 95% CI [1.28, 2.73]), cachexia (HR = 2.39, 95% CI [1.64, 3.49]), and refractory cachexia (HR = 2.87, 95% CI [2.01, 4.10]) compared to people without cachexia.^123^

An NRCS found worse overall survival among those in the high compared to low cachexia risk group using an algorithm that combined the GNRI and sarcopenia (HR = 3.35, 95% CI [2.17, 5.17]).^142^ One study reported worse overall survival for patients with cachexia (a combination of mid-arm muscle area and hand grip strength to identify cachexia) compared to those without (HR = 2.8, 95% CI [1.30, 6.13]).^144^ One study used an investigator-developed algorithm based on a combination of several published definitions of cachexia and found worse overall survival for patients with advance gastric cancer who developed cachexia within 6 months of chemotherapy compared to those who did not (HR = 1.34, 95% CI [1.16, 2.09]).^143^ Another study reported worse overall survival (HR = 7.80, 95% CI [1.43, 42.48]) in the high cancer cachexia risk group (investigator-developed nomogram) compared to the low cachexia risk group.^75^ An NRCS found no significant difference in overall survival between people with non-small lung cancer classified as cachectic (combined Evans 2008 and Fearon 2011 algorithms) and those who were noncachectic (HR = 1.27, CI % [0.71, 2.27]).^120^ Another NRCS found no significant difference in overall survival (p NR) between patients with metastatic castrate-resistant prostate cancer classified with cachexia (nutritional status algorithm) compared to those classified as well nourished.^137^

Two studies reported significantly worse progression-free survival among people with cachexia. One NRCS found worse progression-free survival among those in the high compared to low cachexia risk group using a combination of the GNRI and sarcopenia (HR = 2.77, 95% CI [1.83, 4.12]) ^142^ An NRCS of people with non-small lung cancer found significantly worse progression-free survival in cachectic patients (combined Evans 2008 and Fearon 2011 algorithms) compared to noncachectic patients (HR = 1.64, 95% CI [1.06, 2.55]).^120^

Two studies reported worse disease-free survival among people with cachexia. One study reported worse disease-free survival for people classified to the severe cachexia group compared to those with moderate or mild cachexia by the Cancer Cachexia Score (HR = 2.33, 95% CI [1.55, 3.51]).^115^ A study of patients with cancers of the head and neck reported worse disease-free survival (2.8, 95% CI [1.38, 5.82]) for patients with cachexia (a combination of mid-arm muscle area and hand grip strength to identify cachexia) compared to those without.^144^

One study reported worse relapse-free survival (HR = 4.79, 95% CI [1.80, 12.78]) in the high cancer cachexia risk group (investigator-developed nomogram) compared to the low cachexia risk group.^75^ One study reported worse health-related quality of life between patients with metastatic castrate-resistant prostate cancer classified with cachexia (nutritional status algorithm) compared to those classified as well nourished (OR = 1.75, 95% CI [0.37, 8.33]).^137^

## COMPARISONS BETWEEN ALGORITHMS

Three studies found worse overall mortality for patients identified as cachectic using the Evans 2008 criteria compared to the Fearon 2011 algorithm or a modified form of this (HR = 3.32, 95% CI [2.15, 5.14] vs 1.82 [1.19, 2.77]; 2.82 [1.45, 5.48] vs 2.37 [1.174, 4.764]; and 4.2 [1.7, 10.0] vs 2.93 [1.03, 8.34], p NR for all).^78,^ ^88,^ ^102^ One study found greater mortality in patients identified as cachectic using the CXI algorithm compared to Fearon 2011 (HR = 2.22, 95% CI [1.45, 3.45] vs 0.99 [0.65, 1.52], p NR).^46^ One study found worse mortality in patients identified as cachectic using the Fearon 2006 algorithm compared to Fearon 2011 (HR = 2.26, 95% CI [1.18, 4.32] vs 1.54 [0.88, 2.71], p NR).^49,^ ^76^ Another study reported similar overall mortality for patients identified as cachectic using the Vigano and Wallengren algorithms (HR = 2.39, 95% CI [1.64, 3.49] vs 2.21, 95% CI [1.86, 2.62], p NR).^123^ No study compared algorithms for outcomes related to function, hospitalization, symptom burden, cachexia progression, or feeding tube placement.