# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from the VHA Nutrition Field Advisory Board and our technical expert panel (TEP), which included individuals from the VHA Nutrition & Food Services and Geriatrics & Extended Care, to refine the key questions (KQ). We focus on studies that report classification or staging algorithms for cancer cachexia, their performance metrics, and the clinical and patient-important health outcomes based on these classification algorithms. We define classification or staging algorithms as those that use more than 1 criterion or variable to classify cancer cachexia and that use measures beyond weight. We excluded cancer cachexia algorithms that used only single predictors or variables, including single laboratory measures or imaging techniques.

## KEY QUESTIONS AND PROTOCOL

The following key questions were the focus of this review:

Key Question 1 | What cancer cachexia classification algorithms have been described and what criteria have been used to develop these?
Key Question 2 | What are their performance characteristics?
Key Question 3 | What are the short- and long-term outcomes for patients following cachexia classification with the tools identified in KQ1?

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023458540 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42023458540)).

## SEARCHING AND STUDY SELECTION

We conducted a preliminary search in Medline (via PubMed) that was focused on Medical Subject Headings (MeSH) terms specific to cachexia, cancer, classification, and measures, with confirmation that several known relevant publications were captured. We also explored and adopted aspects of search strategies from several existing systematic reviews relating to the terms specified as appropriate.^5,^ ^21–36^

For our final searches, we searched Medline, Embase, the Cochrane library, and ClinicalTrials.gov from dates of inception to August 1, 2023 (see Appendix for complete search strategies). For the final searches, we used MeSH and free text terms for cachexia, emaciation, and wasting syndrome; terms specific to cancer, including neoplasm, carcinoma, and tumor; and terms relating to classification systems, including severity assessment, prognostic factor, or staging. Additional citations were identified from hand-searching reference lists of relevant systematic reviews and consultation with experts.

Citations were entered into EndNote where duplicates were removed. Remaining citations were screened in Systematic Review Data Repository (SRDR+) (https://srdrplus.ahrq.gov/). To ensure common understanding of the eligibility criteria, we ran 3 pilot rounds of 100 citations each, where all team members screened the same citations, until we achieved acceptable agreement. After the pilot rounds, we screened citations in duplicate. Conflicts that arose between screeners were adjudicated by discussion with the research team or by the lead researcher. Abstracts were excluded if they used the term cachexia (to describe presence or absence) but did not name the cachexia tool used or describe the components used to define cachexia. We also excluded abstracts that did not mention any outcomes of interest. Accepted abstracts underwent full-text review by 2 independent reviewers; an additional team member was consulted to resolve conflicts as necessary. A list of studies extracted at full-text review, along with the reason for their exclusion, can be found in Appendix.

Study eligibility criteria are listed in Table 1. For all KQs, eligible studies included people ≥18 years of age with any type of cancer. Studies had to evaluate cancer cachexia diagnostic or classification algorithms that included multiple predictors or variables to define or stage cachexia. Evaluations of single measures (eg, weight loss, laboratory values, imaging findings) were excluded.

For KQs 1 and 2, our focus was on reporting the components (eg, weight and albumin) and performance characteristics (eg, sensitivity and specificity) of cancer cachexia classification algorithms. We included any study design, including validation studies, randomized controlled trials (RCTs), nonrandomized comparative studies (NRCSs), and single group studies.

For KQ3, eligible studies reported the association between cachexia stage using a classification algorithm described for KQ1 that compared either cachexia stages or cachexia diagnosis (ie, versus no cachexia). For KQ 3, the study could be of any design, but the study had to report on analyses that compared cachexia stages or cachexia to no cachexia (as defined by the evaluated algorithm). We excluded studies that describe cachexia algorithms that included outcomes of interest as part of their classification algorithm (eg, if a quality of life measure was included in the cachexia algorithm and then also assessed the same quality of life measure in the outcomes). Finally, studies had to use an analytic method to account for confounding between cancer cachexia and the prioritized outcomes (eg, inclusion of potential confounders in multivariable regression).

Table 1 Eligibility Criteria

| Inclusion Criteria | Exclusion Criteria
Population | KQ1, 2, & 3: Adults (≥18 years) with any type of cancer at risk for cachexia or with cachexia. | - Non-cancer populations; - Non-humans; - Studies in children
Exposure (Algorithm) | KQ1 & 2:; - Cancer cachexia diagnostic strategies, screening, and classification/severity scoring algorithms (including modified algorithms); - Studies that identify patients as having cachexia using a multicriteria classification algorithm but only use weight to determine stage are included if they meet all other inclusion/exclusion criteria.; - Studies that use multiple laboratory measurements or biomarkers but do not include any other clinical information for classification are included if they meet all other inclusion/exclusion criteria.; KQ 3:; - Cachexia stage or diagnosis as determined by a described algorithms eligible for KQ1 | - Studies evaluating only individual predictors/variables, individual laboratory tests, strategies that solely rely on weight measures (eg, weight change, BMI, serum albumin); - Studies evaluating sarcopenia or malnutrition classification algorithms without mention of cachexia (in title or abstract at screening level); - Classification algorithms using single imaging or single lab techniques without any other accompanying classification criteria; - Studies that analyze cachexia as present/absent but do not provide criteria for this definition in the abstract and did not report outcomes interest in the abstract; - Undefined cachexia classification system (eg, ICD code, use of the term “cachexia” without naming a tool/algorithm or description of components); - Tools that use outcomes as part of their staging/classification definitions
Comparator | KQ1 & 2: None, reference standard, alternate classification algorithms.; KQ3: Lower cachexia stage or classification of no cachexia.
Outcomes | KQ1 & 2; - Components for classification; - Performance measures; KQ3; - Survival (overall, cancer specific, etc); - Cachexia symptom burden/severity (anorexia, nausea, vomiting); - Functional levels (quality of life, Eastern Cooperative Oncology Group Score, Karnofsky Performance Scale Index, Activities of Daily Living, measures of mobility, exercise tolerance, fatigue, etc); - Hospitalizations; - Feeding tube placement (including location and type); - Cachexia progression
Timing | KQ1, 2, & 3: Any
Setting | KQ1, 2, & 3: Any
Study Design | KQ1, 2, & 3; - Validation; - RCT; - NRCS; - Single group studies; KQ1 & 2; - N ≥ 10; KQ3; - Studies that evaluate the association between cachexia tools and eligible outcomes in multivariable regression models, and that explicitly report the association between the tool and the outcome; - N ≥ 10 per cachexia group | KQ1 & 2; - Protocols; - Conference abstracts or other non-peer-reviewed sources; KQ3; - Unadjusted associations between tools and outcomes

Abbreviations. KQ=key question; NRCS=non-randomized comparative study; RCT=randomized controlled trial.

## DATA EXTRACTION AND RISK OF BIAS ASSESSMENT

For all KQs, we extracted details about the study design, total sample size, and the cachexia assessment algorithm used. For KQs 1 and 2, we extracted details on the components of the cancer cachexia classification algorithm, coding or scoring scheme, and cutoffs used. Performance characteristics were collected for studies that compared algorithms against a reference standard of either clinical exam or another cachexia algorithm, including sensitivity, specificity, positive and negative predictive values, and interrater reliability and correlation measures. For KQ3, we extracted details on study design, baseline population characteristics, and prioritized outcomes (survival, function, hospitalization, cachexia progression and symptom burden, and feeding tube placement). For all KQs, all data extraction was first completed by 1 reviewer and then confirmed by a second reviewer, with consultation from other team members as needed to resolve conflicts.

For KQ3, study risk of bias was independently assessed by 1 reviewer using questions derived from the Risk of Bias In Non-randomized Studies – of Interventions tool (see Appendix). We additionally evaluated whether the article was free of discrepancies and adequately reported patient eligibility criteria, protocols, setting, and outcome assessments. Studies had low risk of bias if they used propensity score adjustment and had ≤1 other concern. Studies had moderate risk if they used a multivariable regression to adjust for confounding and had ≤1 other concern or if they used propensity score adjustment and had 2 concerns for bias in other domains. Studies were high risk of bias if there were concerns about the adjustment used, used a propensity score but had ≥2 other concerns, or used multivariable regression and had ≥2 concerns for bias in other domains.

## SYNTHESIS

For KQ1 and 2, we described the features of the classification algorithm including their scoring and performance characteristics. For KQ3, we extracted results data from reported multivariable regression models including odds ratios (OR), risk ratios (RR), hazard ratios (HR), or beta coefficients. Where there were at least 3 studies reporting results from sufficiently similar analyses (based on population, interventions, comparators, and outcomes), we conducted random-effects meta-analyses using the meta package for R version 4.3.0 (R Foundation for Statistical Computing, Vienna, Austria).^37^ Statistical heterogeneity was estimated using restricted maximum-likelihood estimation (REML) and is reported using the I^2^ statistic, which is the proportion of all variability in effects (within and between studies) that is attributable to between-study variation (ie, heterogeneity). We used the GRADE (Grading of Recommendations Assessment, Development and Evaluation) methodology to determine certainty of evidence for cachexia algorithms that had 3 or more comparative studies.