# BACKGROUND

Cachexia is a progressive wasting syndrome characterized by loss of weight and muscle mass,^1^ as well as accompanying changes in inflammatory and metabolic processes.^2–4^ A recent systematic review estimated that more than half of cancer patients in the United States (US) develop cachexia.^5^ Cancer cachexia is associated with poor outcomes including mortality, reduced quality of life, and decreased physical and psychological functioning.^6–8^ Cancer cachexia is also associated with increased hospital length of stay and health care costs.^8,^ ^9^ Generally, the prevalence of cachexia is higher in more advanced stages of cancer.^10,^ ^11^ More advanced cancer cachexia stages may be associated with worse clinical, person-centered, and health care utilization outcomes.^12,13^ There may, therefore, be a benefit to understanding the different cachexia staging tools available in order to identify people who may be at risk for worse outcomes. Cachexia management generally focuses on appetite improvement through nutritional interventions; however, this does not address all aspects of the disorder. Other interventions may include medications for anorexia or physical activity, but there are currently no proven management strategies for cachexia.^2^

There are multiple proposed tools or algorithms to diagnose and stage cancer cachexia.^14^ These algorithms use a variety of criteria or measures, some of which may not be easily obtained in routine clinical settings.^15^ For example, a computed tomography (CT) scan for sarcopenia might require an additional scan beyond what is ordered for the underlying cancer, or these images may be obtained for other clinical purposes but not evaluated for sarcopenia. In addition, some strategies use only a limited number of components or stages to define cachexia, which may oversimplify staging of these patients by assuming equal risk of poor outcomes within these groups.^15^ Malnutrition screening tools are sometimes used to stage cachexia, despite malnutrition and cachexia being separate diagnoses.^16^ While weight loss, malnutrition, and sarcopenia are all intertwined with cachexia, they do not individually encompass the diagnosis of cancer cachexia. For example, patients may experience muscle loss without loss of adipose tissue or may experience fluid accumulation (and thus weight gain) related to cancer or its treatments.^1,^ ^4^ In these situations, weight change alone may not detect cachexia. More recent literature has highlighted the potential for biomarkers to help identify cachexia before clinical signs appear;^17^ although, to date, no biomarker has been validated for cachexia diagnosis.

Although multiple cancer cachexia diagnostic and staging algorithms are available, it remains unclear whether classifying patients based on any of the algorithms is associated with clinical and patient-important outcomes. There is also little guidance available for diagnosing the severity of cancer cachexia. As an integrated health system for 9 million Veterans, the Department of Veterans Affairs (VA) diagnoses over 50,000 Veterans with cancer annually^18^ and is committed to the whole health of Veterans.^19,^ ^20^ Because cachexia may impact cancer outcomes, VA is interested in systematic ways to diagnose, treat, and mitigate cancer cachexia. The Veterans Health Administration (VHA) Nutrition Field Advisory Board requested the present review of evidence on classification systems for staging cancer cachexia among adults and the short- and long-term outcomes associated with cachexia stages using the classification systems. We first describe the classification algorithms that have been published and the performance of these algorithms, then synthesize available evidence on the association between cachexia and clinical and patient-important outcomes. The Nutrition Field Advisory Board intends to use the findings of this review to inform guidance on strategies to identify and stage patients with cancer cachexia across the VA.