# ACKNOWLEDGMENTS

The authors are grateful to Gaelen Adam, PhD, MLIS for literature searching, Maryam Khademi for text retrieval, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Katherine Petersen, MS, RD, CSO, CNSC
  Chair, Oncology Nutrition Clinical Subcommittee
  VHA Nutrition Field Advisory Board

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Mary Chew, MS, RDN
  Acting Clinical Nutrition Manager
  Phoenix VA Health Care System
- Jose M. Garcia, MD PhD
  Professor, Department of Medicine
  Division of Gerontology & Geriatric Medicine
  University of Washington School of Medicine
  Director, Geriatric Research, Education and Clinical Center
  Director, Clinical Research Unit
  VA Puget Sound Health Care System
- Michael J Kelley, MD
  Executive Director, National Oncology Program
  Specialty Care Services, VHA, Dept of Veterans Affairs
  Chief, Hematology/Oncology
  Durham VAMC
  Professor of Medicine
  Duke University
- Brittany Leneweaver, RD, CSO
  Advanced Practice Oncology Dietitian
  Orlando VA Healthcare System
- Brian Mikolasko, MD HMDC
  Palliative Physician
  Hope Health