# ABBREVIATIONS TABLE

Abbreviation: Definition
AUC: Area under the curve
BMI: Body mass index
CAS: Cachexia assessment scale
CASCO: Cachexia score
CRP: C-reactive protein
CT: Computed tomography
CI: Confidence interval
CXI: Cachexia Index
CCSG: Cancer cachexia study group
CSS: Cachexia staging score
CCSI: Cancer Cachexia Staging Index
ECOG-PS: Eastern Cooperative Oncology Group Performance Status
ECOG: Eastern Cooperative Oncology Group
EORTC: European Organization for Research and Treatment of Cancer
ESAS: Edmonton Symptom Assessment System
ESP: Evidence Synthesis Program
GLIM: Global Leadership Initiative on Malnutrition
GNRI: Geriatric nutritional risk index
GPS: Glasgow Prognostic Score
HR: Hazard ratio
KQ: Key questions
L3-SMI: L3 skeletal muscle index
MeSH: Medical subject headings
MUST: Malnutrition universal screening tool
MST: Malnutrition screening tool
NRCS: Nonrandomized comparative studies
NLR: Neutrophil to lymphocyte ratio
NRS: Nutritional risk screening
NS: Nutrition screening
OR: Odds ratio
PG-SGA: Patient-generated subject global assessment
PM-SMI: PM skeletal muscle index
QLQ-C30: Quality of life questionnaire C30
REML: Restricted maximum-likelihood estimation
R-CSS: Radiotherapy cachexia staging score
RCT: Randomized controlled trial
SARC-F: Strength, assistance walking, rising from a chair, climbing stairs, and falls
SNAQ: Short nutritional assessment questionnaire
SMI: Skeletal muscle index
SRDR+: Systematic Review Data Repository
WBC: White blood cell
VA: Veterans Affairs
VAS: Visual analogue scale
VHA: Veterans Health Administration
US: United States
TEP: Technical expert panel