# References

1 National Organization for Arts in Health. Arts, Health, and Well-Being in America. In: Author San Diego, CA; 2017.
2 National Coalition of Creative Arts Therapies Associations I. 2019; https://www.nccata.org/.
3 Ruiz MI, Aceituno D, Rada G. Art therapy for schizophrenia? Medwave. 2017;17(0717-6384 (Electronic)):e6845.28112711
4 Blomdahl C, Gunnarsson AB, Guregård S, Björklund A. A realist review of art therapy for clients with depression. The Arts in Psychotherapy S2- Art Psychotherapy. 2013;40(3):322–330.
5 Kongkasuwan R, Voraakhom K, Pisolayabutra P, Maneechai P, Boonin J, Kuptniratsaikul V. Creative art therapy to enhance rehabilitation for stroke patients: a randomized controlled trial. Clinical rehabilitation. 2016;30(1477-0873 (Electronic)):1016–1023.26396163
6 Miake-Lye IM, Hempel S, Shanman R, Shekelle PG. What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Systematic reviews. 2016;5:28.26864942
7 DistillerSR Evidence Partners, Ottawa, Canada.
8 American Psychiatric Association. DSM History. 2018; https://www.psychiatry.org/psychiatrists/practice/dsm/history-of-the-dsm
9 Tasca C, Rapetti M, Carta MG, Fadda B. Women and hysteria in the history of mental health. Clin Pract Epidemiol Ment Health. 2012;8:110–119.23115576
10 (3ie) IIfIE. 2019; https://www.3ieimpact.org/.
11 Geue K, Rieckhof S, Buttstaedt M, Singer S. Do cancer patients with high levels of distress benefit more than less distressed patients from outpatient art therapy? European journal of oncology nursing : the official journal of European Oncology Nursing Society. 2017;30(1532-2122 (Electronic)):1–7.29031305
12 Bozcuk H, Ozcan K, Erdogan C, Mutlu H, Demir M, Coskun S. A comparative study of art therapy in cancer patients receiving chemotherapy and improvement in quality of life by watercolor painting. Complementary therapies in medicine. 2017;30(1873-6963 (Electronic)):67–72.28137529
13 Lefevre C, Ledoux M, Filbet M. Art therapy among palliative cancer patients: Aesthetic dimensions and impacts on symptoms. Palliative & supportive care. 2016;14(1478-9523 (Electronic)):376–380.26584521
14 Rhondali W, Lasserre E, Filbet M. Art therapy among palliative care inpatients with advanced cancer. Palliative medicine. 2013;27(1477-030X (Electronic)):571–572.23685771
15 Lawson LM, Williams P, Glennon C, . Effect of art making on cancer-related symptoms of blood and marrow transplantation recipients. Oncology nursing forum. 2012;39(1538-0688 (Electronic)):E353–360.22750906
16 Lin MH, Moh SL, Kuo YC, . Art therapy for terminal cancer patients in a hospice palliative care unit in Taiwan. Palliative & supportive care. 2012;10(1478-9523 (Electronic)):51–57.22329937
17 Ho RT, Potash JS, Fu W, Wong KP, Chan CL. Changes in breast cancer patients after psychosocial intervention as indicated in drawings. Psycho-oncology. 2010;19(1099-1611 (Electronic)):353–360.19358159
18 Bar-Sela G, Atid L, Danos S, Gabay N, Epelbaum R. Art therapy improved depression and influenced fatigue levels in cancer patients on chemotherapy. Psycho-oncology. 2007;16(1057-9249 (Print)):980–984.17351987
19 Nainis N, Paice JA, Ratner J, Wirth JH, Lai J, Shott S. Relieving symptoms in cancer: innovative use of art therapy. Journal of pain and symptom management. 2006;31(0885-3924 (Print)):162–169.16488349
20 Geue K, Richter R, Buttstadt M, Brahler E, Singer S. An art therapy intervention for cancer patients in the ambulant aftercare - results from a non-randomised controlled study. European journal of cancer care. 2013;22(1365-2354 (Electronic)):345–352.23331300
21 Singer S, Gotze H, Buttstadt M, . A non-randomised trial of an art therapy intervention for patients with haematological malignancies to support post-traumatic growth. Journal of health psychology. 2013;18(1461-7277 (Electronic)):939–949.23027781
22 Radl D, Vita M, Gerber N, Gracely EJ, Bradt J. The Effects of Self-Book(c) Art Therapy on Cancer-Related Distress in Female Cancer Patients during Active Treatment: A Randomized Controlled Trial. Psycho-oncology. 2018(1099-1611 (Electronic)).
23 Thyme KE, Sundin EC, Wiberg B, Oster I, Astrom S, Lindh J. Individual brief art therapy can be helpful for women with breast cancer: a randomized controlled clinical study. Palliative & supportive care. 2009;7(1478-9523 (Electronic)):87–95.19619378
24 Svensk AC, Oster I, Thyme KE, . Art therapy improves experienced quality of life among women undergoing treatment for breast cancer: a randomized controlled study. European journal of cancer care. 2009;18(1365-2354 (Electronic)):69–77.19473224
25 Oster I, Svensk AC, Magnusson E, . Art therapy improves coping resources: a randomized, controlled study among women with breast cancer. Palliative & supportive care. 2006;4(1478-9515 (Print)):57–64.16889324
26 Radl DM. The effects of Self-Book(c) art therapy on emotional distress in female cancer patients: A randomized controlled trial. Dissertation Abstracts International: Section B: The Sciences and Engineering S2- Dissertation Abstracts International. 2016;76(9-B(E)).
27 Warson E. Healing pathways: art therapy for American Indian cancer survivors. Journal of cancer education : the official journal of the American Association for Cancer Education. 2012;27(1543-0154 (Electronic)):S47–56.22311692
28 Arruda MA, Garcia MA, Garcia JB. Evaluation of the Effects of Music and Poetry in Oncologic Pain Relief: A Randomized Clinical Trial. Journal of palliative medicine. 2016;19(1557-7740 (Electronic)):943–948.27529806
29 Wood MJ, Molassiotis A, Payne S. What research evidence is there for the use of art therapy in the management of symptoms in adults with cancer? A systematic review. Psycho-oncology. 2011;20(1099-1611 (Electronic)):135–145.20878827
30 Geue K, Goetze H, Buttstaedt M, Kleinert E, Richter D, Singer S. An overview of art therapy interventions for cancer patients and the results of research. Complementary therapies in medicine. 2010;18(1873-6963 (Electronic)):160–170.20688262
31 Archer S, Buxton S, Sheffield D. The effect of creative psychological interventions on psychological outcomes for adult cancer patients: a systematic review of randomised controlled trials. Psycho-oncology. 2015;24(1099-1611 (Electronic)):1–10.
32 Boehm K, Cramer H. Arts therapies for anxiety, depression, and quality of life in breast cancer patients: a systematic review and meta-analysis. 2014;2014(1741-427X (Print)):103297.
33 Puetz TW, Morley CA, Herring MP. Effects of creative arts therapies on psychological symptoms and quality of life in patients with cancer. JAMA internal medicine. 2013;173(2168-6114 (Electronic)):960–969.23699646
34 Kim KS, Loring S, Kwekkeboom K. Use of Art-Making Intervention for Pain and Quality of Life Among Cancer Patients: A Systematic Review. Journal of holistic nursing : official journal of the American Holistic Nurses’ Association. 2017(1552-5724 (Electronic)):898010117726633.
35 Morton A, Forsey P. My Time, My Space (an arts-based group for women with postnatal depression): a project report. Community practitioner : the journal of the Community Practitioners’ & Health Visitors’ Association. 2013;86(1462-2815 (Print)):31–34.
36 Gussak D. The effectiveness of art therapy in reducing depression in prison populations. International journal of offender therapy and comparative criminology. 2007;51(0306-624X (Print)):444–460.17652148
37 Blomdahl C, Guregard S, Rusner M, Wijk H. A manual-based phenomenological art therapy for individuals diagnosed with moderate to severe depression (PATd): A randomized controlled study. Psychiatric rehabilitation journal. 2018(1559-3126 (Electronic)).
38 Ciasca EC, Ferreira RC, Santana CLA, . Art therapy as an adjuvant treatment for depression in elderly women: a randomized controlled trial. Revista brasileira de psiquiatria (Sao Paulo, Brazil : 1999). 2018(1809-452X (Electronic)):0.
39 Nan JKM, Ho RTH. Effects of clay art therapy on adults outpatients with major depressive disorder: A randomized controlled trial. Journal of affective disorders. 2017;217(1573-2517 (Electronic)):237–245.28433887
40 Babouchkina A, Robbins SJ. Reducing negative mood through mandala creation: A randomized controlled trial. Art Therapy. 2015;32(1):34–39.
41 Kimport ER, Robbins SJ. Efficacy of creative clay work for reducing negative mood: A randomized controlled trial. Art Therapy. 2012;29(2):74–79.
42 Thyme KE, Sundin EC, Stahlberg G, Lindstrom B, Eklof H, Wiberg B. The outcome of short-term psychodynamic art therapy compared to short-term psychodynamic verbal therapy for depressed women. Psychoanalytic Psychotherapy. 2007;21(3):250–264.
43 Bell CE, Robbins SJ. Effect of art production on negative mood: A randomized, controlled trial. Art Therapy. 2007;24(2):71–75.
44 Rawtaer I, Mahendran R, Yu J, Fam J, Feng L, Kua EH. Psychosocial interventions with art, music, Tai Chi and mindfulness for subsyndromal depression and anxiety in older adults: A naturalistic study in Singapore. Asia-Pacific psychiatry : official journal of the Pacific Rim College of Psychiatrists. 2015;7(1758-5872 (Electronic)):240–250.26178378
45 Im ML, Lee JI. Effects of art and music therapy on depression and cognitive function of the elderly. Technology and health care : official journal of the European Society for Engineering and Medicine. 2014;22(1878-7401 (Electronic)):453–458.24704654
46 Weiskittle RE, Gramling SE. The therapeutic effectiveness of using visual art modalities with the bereaved: a systematic review. Psychology research and behavior management. 2018;11(1179-1578 (Print)):9–24.29440940
47 Sauer PE, Fopma-Loy J, Kinney JM, Lokon E. “It makes me feel like myself”: Person-centered versus traditional visual arts activities for people with dementia. Dementia (London, England). 2016;15(1741-2684 (Electronic)):895–912.
48 Gross SM, Danilova D, Vandehey MA, Diekhoff GM. Creativity and dementia: does artistic activity affect well-being beyond the art class? Dementia (London, England). 2015;14(1741-2684 (Electronic)):27–46.
49 Witkoski SA, Chaves MLF. Evaluation of artwork produced by Alzheimer’s disease outpatients in a pilot art therapy program. Dementia & neuropsychologia. 2007;1(1980-5764 (Print)):217–221.29213391
50 Rentz CA. Memories in the making: outcome-based evaluation of an art program for individuals with dementing illnesses. American journal of Alzheimer’s disease and other dementias. 2002;17(1533-3175 (Print)):175–181.
51 Seifert K, Spottke A, Fliessbach K. Effects of sculpture based art therapy in dementia patients-A pilot study. Heliyon. 2017;3(2405-8440 (Print)):e00460.29264417
52 Hattori H, Hattori C, Hokao C, Mizushima K, Mase T. Controlled study on the cognitive and psychological effect of coloring and drawing in mild Alzheimer’s disease patients. Geriatrics & gerontology international. 2011;11(1447-0594 (Electronic)):431–437.21518170
53 Rusted J, Sheppard L, Waller D. A Multi-centre Randomized Control Group Trial on the Use of Art Therapy for Older People with Dementia. Group Analysis. 2006;39(4):517–536.
54 Kang HY, Bae YS, Kim EH, Lee KS, Chae MJ, Ju RA. An integrated dementia intervention for Korean older adults. Journal of psychosocial nursing and mental health services. 2010;48(0279-3695 (Print)):42–50.
55 Ozdemir L, Akdemir N. Effects of multisensory stimulation on cognition, depression and anxiety levels of mildly-affected Alzheimer’s patients. Journal of the neurological sciences. 2009;283(1878-5883 (Electronic)):211–213.19289242
56 Pongan E, Tillmann B, Leveque Y, . Can Musical or Painting Interventions Improve Chronic Pain, Mood, Quality of Life, and Cognition in Patients with Mild Alzheimer’s Disease? Evidence from a Randomized Controlled Trial. Journal of Alzheimer’s disease : JAD. 2017;60(1875-8908 (Electronic)):663–677.28922159
57 Cowl AL, Gaugler JE. Efficacy of creative arts therapy in treatment of Alzheimer’s disease and dementia: A systematic literature review. Activities, Adaptation & Aging. 2014;38(4):281–330.
58 Beard RL. Art therapies and dementia care: A systematic review. Dementia: The International Journal of Social Research and Practice. 2012;11(5):633–656.
59 Qiu HZ, Ye ZJ, Liang MZ, Huang YQ, Liu W, Lu ZD. Effect of an art brut therapy program called go beyond the schizophrenia (GBTS) on prison inmates with schizophrenia in mainland China-A randomized, longitudinal, and controlled trial. Clinical psychology & psychotherapy. 2017;24(1099-0879 (Electronic)):1069–1078.28078741
60 Montag C, Haase L, Seidel D, . A pilot RCT of psychodynamic group art therapy for patients in acute psychotic episodes: feasibility, impact on symptoms and mentalising capacity. PloS one. 2014;9(1932-6203 (Electronic)):e112348.25393414
61 Leurent B, Killaspy H, Osborn DP, . Moderating factors for the effectiveness of group art therapy for schizophrenia: secondary analysis of data from the MATISSE randomised controlled trial. Pain Med 2014 Apr;15: Suppl 1:S66-75 doi: 101111/pme12409. 2014;49(1433-9285 (Electronic)):1703–1710.
62 Richardson P, Jones K, Evans C, Stevens P, Rowe A. Exploratory RCT of art therapy as an adjunctive treatment in schizophrenia. Journal of Mental Health. 2007;16(4):483–491.
63 Attard A, Larkin M. Art therapy for people with psychosis: a narrative review of the literature. The lancet Psychiatry. 2016;3(2215-0374 (Electronic)):1067–1078.27528095
64 Ruddy R, Milnes D. Art therapy for schizophrenia or schizophrenia-like illnesses. The Cochrane database of systematic reviews. 2005(1469-493X (Electronic)):Cd003728.16235338
65 Campbell M, Decker KP, Kruk K, Deaver SP. Art Therapy and Cognitive Processing Therapy for Combat-Related PTSD: A Randomized Controlled Trial. Art therapy : journal of the American Art Therapy Association. 2016;33(0742-1656 (Print)):169–177.29332989
66 Wang X, Lan C, Chen J, Wang W, Zhang H, Li L. Creative arts program as an intervention for PTSD: a randomized clinical trial with motor vehicle accident survivors. International journal of clinical and experimental medicine. 2015;8(1940-5901 (Print)):13585–13591.26550298
67 Baker FA, Metcalf O, Varker T, O’Donnell M. A Systematic Review of the Efficacy of Creative Arts Therapies in the Treatment of Adults With PTSD. Psychological trauma : theory, research, practice and policy. 2017(1942-969X (Electronic)).
68 Lee JY, Kim H, Kim S, Choe K, Kim JS. Effects of Mandala Art Therapy on Subjective Well-being, Resilience, and Hope in Psychiatric Inpatients. International journal of environmental research and public health. 2018;32(1532-8228 (Electronic)):167–173.
69 Brady C, Moss H, Kelly BD. A fuller picture: evaluating an art therapy programme in a multidisciplinary mental health service. Medical humanities. 2017;43(1473-4265 (Electronic)):30–34.27670973
70 Gussak D. Art therapy with prison inmates: A pilot study. The Arts in psychotherapy. 2004;31:245–259.
71 Gantt L, Tinnin LW. Intensive trauma therapy of PTSD and dissociation: An outcome study. J The Arts in Psychotherapy. 2007;34(1):69–80.
72 Brooke SL. Art therapy: An approach to working with sexual abuse survivors. J The Arts in Psychotherapy. 1995.
73 Kaimal G, Jones J, Dieterich-Hartwell R, Acharya B, Wang X. Evaluation of long- and short-term art therapy interventions in an integrative care setting for military service members with post-traumatic stress and traumatic brain injury. The Arts in psychotherapy. 2018.
74 Haeyen S, van Hooren S, van der Veld W, Hutschemaekers G. Efficacy of Art Therapy in Individuals With Personality Disorders Cluster B/C: A Randomized Controlled Trial. Journal of personality disorders. 2017(1943-2763 (Electronic)):1–16.
75 Crawford MJ, Killaspy H, Kalaitzaki E, . The MATISSE study: a randomised trial of group art therapy for people with schizophrenia. BMC psychiatry. 2010;10(1471-244X (Electronic)):65.20799930
76 Crawford MJ, Killaspy H, Barnes TR, . Group art therapy as an adjunctive treatment for people with schizophrenia: multicentre pragmatic randomised trial. BMJ (Clinical research ed). 2012;344(1756-1833 (Electronic)):e846.
77 Crawford MJ, Killaspy H, Barnes TR, . Group art therapy as an adjunctive treatment for people with schizophrenia: a randomised controlled trial (MATISSE). Health technology assessment (Winchester, England). 2012;16(2046-4924 (Electronic)):iii–iv, 1–76.
78 Green BL, Wehling C, Talsky GJ. Group art therapy as an adjunct to treatment for chronic outpatients. Hospital & community psychiatry. 1987;38(0022-1597 (Print)):988–991.3679106
79 Theorell T, Konarski K, Westerlund H, . Treatment of patients with chronic somatic symptoms by means of art psychotherapy: a process description. Psychotherapy and psychosomatics. 1998;67(0033-3190 (Print)):50–56.9491441
80 Schut HA, de Keijser J, van den Bout J, Stroebe MS. Cross-modality grief therapy: description and assessment of a new program. Journal of clinical psychology. 1996;52(0021-9762 (Print)):357–365.8835699
81 Odell-Miller H, Hughes P, Westacott M. An investigation into the effectiveness of the arts therapies for adults with continuing mental health problems. Psychotherapy Research. 2006;16(1):122–139.
82 Uttley L, Stevenson M, Scope A, Rawdin A, Sutton A. The clinical and cost effectiveness of group art therapy for people with non-psychotic mental health disorders: a systematic review and cost-effectiveness analysis. BMC psychiatry. 2015;15(1471-244X (Electronic)):151.26149275
83 Schouten KA, de Niet GJ, Knipscheer JW, Kleber RJ, Hutschemaekers GJ. The effectiveness of art therapy in the treatment of traumatized adults: a systematic review on art therapy and trauma. Trauma, violence & abuse. 2015;16(1552-8324 (Electronic)):220–228.
84 Rao D, Nainis N, Williams L, Langner D, Eisin A, Paice J. Art therapy for relief of symptoms associated with HIV/AIDS. AIDS care. 2009;21(1360-0451 (Electronic)):64–69.19085221
85 Sudres J-L, Anzules C, Sanguignol F, Pataky Z, Brandibas G, Golay A. Therapeutic patient education with art therapy: Effectiveness among obese patients. Education Thérapeutique du Patient / Therapeutic Patient Education. 2013;5(2):213–218.
86 Bae YS, Kim DH. The Applied Effectiveness of Clay Art Therapy for Patients With Parkinson’s Disease. Journal of evidence-based integrative medicine. 2018;23(2515-690X (Electronic)):2515690x18765943.
87 Ali K, Gammidge T, Waller D. Fight like a ferret: a novel approach of using art therapy to reduce anxiety in stroke patients undergoing hospital rehabilitation. Medical humanities. 2014;40(1473-4265 (Electronic)):56–60.24429732
88 Kim MK, Kang SD. Effects of art therapy using color on purpose in life in patients with stroke and their caregivers. Yonsei medical journal. 2013;54(1976-2437 (Electronic)):15–20.23225793
89 Beauchet O, Remondiere S, Mahe M, Repussard F, Decavel F, Annweiler C. Geriatric inclusive art and length of stay in acute care unit: a case-control pilot study. Journal of the American Geriatrics Society. 2012;60(1532-5415 (Electronic)):1585–1587.22889027
90 Caddy L, Crawford F, Page AC. ‘Painting a path to wellness’: correlations between participating in a creative activity group and improved measured mental health outcome. Journal of psychiatric and mental health nursing. 2012;19(1365-2850 (Electronic)):327–333.22074391
91 Hughes EG, da Silva AM. A pilot study assessing art therapy as a mental health intervention for subfertile women. Human reproduction (Oxford, England). 2011;26(1460-2350 (Electronic)):611–615.
92 Sacchett C, Byng S, Marshall J, Pound C. Drawing together: evaluation of a therapy programme for severe aphasia. International journal of language & communication disorders. 1999;34(1368-2822 (Print)):265–289.10884902
93 Elkis-Abuhoff D, Goldblatt R, Gaydos M, Corrato S. Effects of clay manipulation on somatic dysfunction and emotional distress in patients with Parkinson’s disease. Art Therapy: Journal of the American Art Therapy Association. 2008;25(3):122–128.
94 Elkis-Abuhoff DL, Goldblatt RB, Gaydos M, Convery C. A pilot study to determine the psychological effects of manipulation of therapeutic art forms among patients with Parkinson’s disease. International Journal of Art Therapy. 2013;18(3):113–121.
95 Trzaska JD. The use of a group mural project to increase self-esteem in high-functioning, cognitively disabled adults. The Arts in psychotherapy. 2012;39(5):436–442.
96 Hamre HJ, Witt CM, Glockmann A, Ziegler R, Willich SN, Kiene H. Anthroposophic art therapy in chronic disease: a four-year prospective cohort study. Explore (New York, NY). 2007;3(1550-8307 (Print)):365–371.
97 Birch MA. The health benefits of art therapy following traumatic life experiences. Dissertation Abstracts International: Section B: The Sciences and Engineering S2- Dissertation Abstracts International. 1998;58(11-B):6226.
98 Field W, Kruger C. The effect of an art psychotherapy intervention on levels of depression and health locus of control orientations experienced by black women living with HIV. J South African Journal of Psychology. 2008;38(3):467–478.
99 Stuckey HL, Nobel J. The connection between art, healing, and public health: a review of current literature. American journal of public health. 2010;100(1541-0048 (Electronic)):254–263.20019311
100 Reynolds MW, Nabors L, Quinlan A. The effectiveness of art therapy: Does it work? Art Therapy. 2000;17(3):207–213.
101 Chu KY, Huang CY, Ouyang WC. Does Chinese calligraphy therapy reduce neuropsychiatric symptoms: a systematic review and meta-analysis. BMC psychiatry. 2018;18(1471-244X (Electronic)):62.29514660
102 Van Lith T. Art therapy in mental health: A systematic review of approaches and practices. The Arts in Psychotherapy S2- Art Psychotherapy. 2016;47:9–22.