# Summary and Discussion

Many of the systematic reviews focused on a specific health condition but described a number of Creative Arts Therapies. The evidence within reviews was often described as having low methodological quality, lacking details about the therapy itself, the evaluation methods and measures. Despite these issues, preliminary positive effects were described in the majority of systematic reviews for a range of health conditions.

The purpose of this map was to create a navigable, interactive map that would demonstrate the breadth of research across this broad field and its related disciplines. Additional searches using terms specific to the individual disciplines could improve the representation of research for those disciplines within the map. Where high-quality, recent systematic reviews are available, certain areas may be well-represented by existing synthesis efforts; however, more detailed review would be required, which was out of scope for the current effort.

## Research Gaps/Future Research

This evidence mapping process was intended to describe the range of evidence on art therapy. When multiple systematic reviews within the evidence map overlap in coverage, cross-checking of these reviews may be necessary to determine if the same primary studies are being described, the extent of the overlap, and applicability of some or all findings in a review for a particular research or policy question. A future synthesis would be needed to see which studies were included in all reviews, and which were included in some but not others to determine a new finding inclusive of all potential evidence.

For future primary research studies, larger studies with rigorous designs that report their therapy approach and methodological details would be beneficial.

### Relevance to VA Priority Topics

Certain high-priority areas within the VA were represented within the literature included in this evidence map and merit mention. We identified 2 impact evaluations^65,66^ and 1 medium-confidence systematic review^67^ relevant to PTSD, which was included as a stand-alone category within the evidence map. Many of the studies in the mood disorders category related to the priority area of depression, with 1 of the 2 systematic reviews, which was low confidence, also focused on depression.^4^ Other priority areas such as trauma and traumatic brain injury (TBI) did not have enough literature to merit separate categories, and were grouped within the Other Psychiatric health conditions category. One study of PTSD and TBI addressed both these priority areas,^73^ while 1 low-confidence systematic review focused on the priority area of trauma.^83^ The category of cancer/palliation included studies and systematic reviews about cancer-related pain, which address the VA priority area of pain. Aside from 1 systematic review for patients with cancer-related pain,^34^ none of the systematic reviews for VA priorities was appraised as high confidence. High-quality systematic reviews related to these various topic areas would help describe what is known about the effectiveness of art therapy as a treatment in these areas.