# Results

Below we describe the findings from our evidence mapping process. This includes a literature flow, followed by the visual depiction of our evidence map findings, and finally our narrative discussion of the findings.

## Literature Flow

Our searches identified a total of 1,330 references, of which 448 references were excluded after screening titles. After including 3 additional references from peer review experts, 885 references were included for abstract screening. We reviewed these abstracts and collected basic descriptive information when possible. During this abstract screening process a total of 791 references were excluded for the following reasons: reference was for a non-systematic review, commentary, or other publication that did not present original study data (n=197); data presented were exclusively qualitative in nature, such as individual case reports (n=168); references were published before 1980 (n=91); the intervention did not meet our definition of art therapy, as described in the study selection section above (n=77); quantitative analysis was purely descriptive and no evaluative data were presented (n=47); unable to retrieve the full text of the publication to abstract necessary data (n=44); focus of the study was healthy participants (n=25); focus of the study was pediatric populations (n=78); Mindfulness-based Art Therapy (MBAT) (n=6); drama therapy (n=2); and dance therapy (n=1). In categorizing the 94 references included in the evidence map, we identified 19 systematic reviews, 31 RCTs, and 44 impact evaluations that were not RCTs. See Figure 1 for literature flow.

Figure 1 Literature Flow Chart

## Evidence Map

### Interactive Evidence Map on the 3ie Platform

We developed an evidence map for art therapy (see Figure 2), which allows us to visually depict the distribution of evidence available, describing the volume and general characteristics of research in this area. The evidence map displays each of the 94 included references, sorted by health condition and type of study. Systematic reviews are grouped in the green, red, or orange bubbles and impact evaluations, including RCTs and other quantitative evaluations, are grouped in the gray bubbles.

The evidence map in this report can be explored in an interactive way online at http://egmopenaccess.3ieimpact.org/evidence-maps/art-therapy. The online version allows users to view sort citations by different categorizations or to view citations attributed to specific bubbles. All data available in the interactive version of the map is also in this report; to see the citations for any specific bubble, refer to Appendix F. Each bubble has been assigned a coordinate in the report version of the evidence map for ease of identification. This coordinate is assigned a number, based on the corresponding health condition, and a letter, based on the corresponding treatment modality. In cases where there is more than 1 bubble in that map segment, the gray impact evaluation bubbles have a “1” appended to the end of this coordinate, the green systematic reviews bubbles (rated high confidence) have a “3” appended to the end of the coordinate, the orange systematic reviews bubbles (rated medium confidence) have a “4” appended to the end of the coordinate, and the red systematic reviews bubbles (rated low confidence) have a “2” appended to the end of this coordinate.

Figure 2 Evidence Map of Art Therapy Publications

This map is running on the 3ie evidence gap map platform (http://egmopenaccess.3ieimpact.org/evidence-maps/art-therapy) developed by the International Initiative for Impact Evaluation, 3ie. Each bubble has been assigned a color and a coordinate in the evidence map for ease of identification. This coordinate is assigned a number, based on the corresponding health condition, and a letter, based on the treatment modality (“A” for art therapy or “B” for mixture/combination). In cases where there is more than 1 bubble in that map segment, the gray impact evaluation bubbles have a “1” appended to the end of this coordinate, the green systematic reviews bubbles (rated high confidence) have a “3” appended to the end of the coordinate, the orange systematic reviews bubbles (rated medium confidence) have a “4” appended to the end of the coordinate, and the red systematic reviews bubbles (rated low confidence) have a “2” appended to the end of this coordinate.

### Narrative Description of Evidence Map

Below we describe the evidence depicted in the evidence map by health condition. For lists of citations associated with any specific group, please see Appendix F. For the evidence table for systematic reviews, please see Appendix G.

#### Cancer/Palliation

There were 16 impact evaluations of art therapy related to cancer and/or palliation,^11–26^ of which 5 were RCTs.^22–26^ In addition, there were 2 impact evaluations that combined treatment modalities related to cancer/palliation: drawing and breathing exercises,^27^ and music and poetry,^28^ of which 1 was an RCT.^28^

There were 6 systematic reviews related to cancer/palliation that included a mixture of art therapy and other therapy. In terms of confidence in conclusions about effects, 2 were rated low confidence,^29,30^ 3 were rated medium confidence,^31–33^ and 1 was rated high confidence.^34^ The latter study rated high confidence stated that although some studies “reported beneficial effects of art making on pain and [quality of life],” the evidence was weakened by “poor study quality ratings, heterogeneity in art-making interventions and outcome measures, interventions including non–art-making components, and few randomized controlled studies."^34^

#### Mood Disorders

There were 9 impact evaluations of art therapy related to mood disorders,^35–43^ of which 7 were RCTs.^37–43^ In addition, there were 2 impact evaluations related to mood disorders that combined art therapy with tai chi, mindfulness, and music reminiscence^44^, and with music.^45^

There were 2 systematic reviews related to mood disorders that included art therapy. Both were rated low confidence.^4,46^

#### Alzheimer’s/Dementia

There were 7 impact evaluations of art therapy related to Alzheimer’s/dementia,^47–53^ of which 1 was an RCT.^53^ In addition, there were 3 impact evaluations related to Alzheimer’s/dementia that combined art therapy with music, horticulture activity, memory training, and cognitive stimulation activities.^54^ with music,^55^ and with choral singing^56^ of which 1 was an RCT.^56^

There were 2 systematic reviews related to Alzheimer’s/dementia that included a mixture of art therapy and other treatment modality. Both were rated low confidence.^57,58^

#### Schizophrenia/Psychosis

There were 4 impact evaluations of art therapy related to schizophrenia/psychosis, all of which were RCTs.^59–62^

There was 1 systematic review related to schizophrenia/psychosis and art therapy, and it was rated low confidence.^3^ There were 2 systematic reviews related to schizophrenia/psychosis that included a mixture of art therapy and other treatment modalities; 1 was rated medium confidence^63^ and 1 was rated high confidence.^64^ The review rated high confidence reported “a small but significant difference favoring art therapy group” for one of the mental state measures, “no clear difference between groups” for measure of social functioning, and no significant effects of art therapy on quality of life.^64^

#### PTSD

There was 1 impact evaluation of art therapy related to post traumatic stress disorder (PTSD).^65^ In addition, there was 1 impact evaluation related to PTSD that combined art therapy with creative writing.^66^ Both of these studies were RCTs.

There was 1 systematic review related to PTSD that included a mixture of art therapy and other treatment modality. It was rated medium confidence.^67^

#### Other Psychiatric Health Conditions

There were 11 impact evaluations of art therapy related to other psychiatric health conditions,^68–78^ of which 5 were RCTs.^74–78^ In addition, there were 3 impact evaluations related to other psychiatric health conditions that combined art therapy with music, dance, psychodrama,^79^ with grief therapy,^80^ and with music and dance movement therapy,^81^ of which 1 was an RCT.^81^

There were 2 systematic reviews related to other psychiatric health conditions that included a mixture of art therapy and other therapy. Both were rated low confidence.^82,83^

#### Other Non-Psychiatric Health Conditions

There were 13 impact evaluations of art therapy related to other non-psychiatric health conditions,^5,84–95^ of which 3 were RCTs.^76–78^ In addition, there were 3 impact evaluations related to non-psychiatric health conditions that combined art therapy with music and speech exercises,^96^ with writing,^97^ and with doll-making and discussion of films,^98^ of which 1 was an RCT.^97^

There were 3 systematic reviews related to other non-psychiatric health conditions that included a mixture of art therapy and other therapy. Two were rated low confidence,^99,100^ and 1 was rated medium confidence.^101^

### Summary of Systematic Review Findings

Many of the systematic reviews we included in this evidence map focused on a specific health condition but looked broadly across art therapy modalities, with 16 of the 19 included reviews falling into the mixture/combination of modalities categorization. Many noted beneficial or positive effects on health, with none describing harmful effects. Of the 19 systematic reviews included in this map, 2 were appraised as having high confidence in their conclusions. One of these reviews focused on pain and quality of life for patients with cancer.^34^ The second was a Cochrane review of art therapy for schizophrenia or schizophrenia-like illnesses.^64^ In addition to these 2 reviews appraised as high confidence, 6 reviews were appraised as medium confidence and 11 were appraised as low confidence. Findings from systematic reviews of medium or low confidence are reported in the evidence tables (Appendix G).

While almost all the systematic reviews describe some evidence of positive effects on health outcomes, the evidence was often described as having low methodological quality, with 1 systematic review, looking broadly across all therapies for various psychiatric health conditions, explicitly calling for future studies to “incorporate more details on the art therapy approaches.”^102^ Another systematic review focused on dementia that looked across Creative Arts Therapy modalities broadly found similar issues, stating that “this analysis reveals that systematically designed, documented, and evaluated [art therapy] studies are scarce. Information on research design, operational concepts, measurement tools, and methods of evaluation/analysis are vague, if provided.”^58^