# Methods

## Topic Development

This topic was developed in response to a nomination by Donna Faraone, Field Implementation Team Lead and Music Therapist/Office of Patient Centered Care and Cultural Transformation, David Otto, National Program Director/Recreation Therapy Service (10P4RR), and Ben Kligler, National Director/Coordinating Center for Integrative Health. Given the nominators’ interest in an overview of a broad field, an evidence mapping methodology was determined to be most appropriate for their needs.

## Search Strategy

We conducted broad searches from database inception through May 5, 2018 using terms related to art therapy in 2 databases: PubMed and PsycINFO (see Appendix A for full search strategy). We conducted 2 searches specific to study design for randomized controlled trials and systematic reviews, as well as a third, more general search that did not specify a study design.

## Study Selection

All citations were reviewed by 3 independent reviewers (IML, EAA, SSM). Any citation chosen by a single reviewer was advanced to abstract screening. Abstracts were then reviewed on the DistillerSR platform^7^ in duplicate by 2 independent reviewers (IML, EAA, SSM) using an abstract screening form (see Appendix B); discrepancies were resolved through group discussion. If all data elements were captured sufficiently for evidence map categorization, then no full-text review was necessary. For publications where abstract data were insufficient or unclear, data extraction and full-text review were completed by 2 reviewers and verified by a third (IML, EAA, SMM) on DistillerSR using a slightly modified version of the abstract screening form (see Appendix C). All systematic reviews were reviewed in full text. All discrepancies were resolved with full group discussion. In order to be included, references needed to meet the following criteria:

Population: Individuals diagnosed with any medical condition. Reports of art therapy with healthy populations, such as general community members or college students, were excluded since they were not diagnosed with any condition. Pediatric populations were also excluded.

Intervention: Art therapy led by an art therapist, or therapy that combined multiple treatment modalities. Explicit descriptions of therapy led by other professionals or lay people (eg, artists, occupational therapists, nurses, volunteers, or self-led) were excluded. When the therapist/facilitator was unclear or unstated we included the reference. If the art was used for diagnostic, rather than therapeutic, purposes we excluded the reference. Some systematic reviews discussed a variety of treatments, including various Creative Arts Therapies.^1^ If art therapy was included in such a review we would include the review.

Comparator(s)/control: Any

Context: Any health care-related setting

Outcome(s): Patient health outcomes

Timing: Studies published in 1980 or later. Particularly for studies pertaining to mental health outcomes, looking at studies since 1980—when the Diagnostic and Statistical Manual of Mental Disorders (DSM) III was published^8^—allowed for more consistency when referencing mental health diagnoses. The context of mental health care in the United States has evolved to an extent to which older studies may no longer be comparable to newer research. For instance, the diagnosis of posttraumatic stress disorder (PTSD) did not exist prior to the DSM III, and outdated diagnoses such as hysteria were still in use.^9^

Study design: Randomized control trials (RCT), quantitative impact evaluations presenting health outcome data, or systematic reviews. Case reports, descriptive quantitative studies with no health outcome data, and references that did not include original data (eg commentaries, non-systematic reviews) were excluded.

## Data Abstraction

During abstract screening, basic data elements were collected from abstracts when possible, including the study design, intervention, and population (see Appendix B). If all data elements were captured sufficiently for evidence map categorization, then no full-text review was necessary. For publications where abstract data were insufficient or unclear, data extraction and full-text review were completed by 2 reviewers and verified by a third (IML, EAA, SMM) using a slightly modified version of the abstract screening form (see Appendix C). All systematic reviews were subject to full-text data abstraction, in order to capture the number of included studies and the main findings of each review.

Each systematic review was rated as low, medium, or high confidence, using the 3ie system.^10^ Per 3ie’s description: “High, Medium and Low Confidence refers to confidence in conclusions about effects. It indicates the overall rating given to a systematic review based on a careful appraisal of the methods applied in a systematic review, using a standardised checklist.” See Appendix D for the checklist used.

## Data Synthesis

Our evidence mapping process resulted in a visual depiction of the evidence for art therapy, an online interactive map, as well as an accompanying narrative with ancillary figures and tables.

### Evidence Map

The visual depiction uses a bubble plot format to display information on 4 dimensions: x-axis, y-axis, bubble color, and bubble size. This allowed us to provide 4 types of information about each included publication, as follows:

Treatment modality (y-axis): We included studies that employed either art therapy or a mixture/combination of art therapy modalities.

Health condition studied (x-axis): We grouped publications into categories of health conditions that were studied as described in study selection, above. The categories on the x-axis include: Alzheimer’s/dementia, PTSD, mood disorders, cancer/palliation, schizophrenia/psychosis, other psychiatric health conditions, and other non-psychiatric health conditions.

Study design (bubble color): Each bubble is either gray, green, red, or orange. Any individual study, either an RCT or other type of impact evaluation, is included in the gray bubble for the particular health condition/treatment modality combination. Systematic reviews that are rated high confidence are in green, medium confidence in red, and low confidence in orange for their assigned health condition/treatment modality combination.

Number of publications (bubble size): Each bubble’s size is directly proportional to the number of publications included in that study design within a specific health condition/treatment modality combination.

The evidence map figure also allows the reader to visualize gaps in the literature base, where there is no or little evidence for particular health conditions or treatment modalities.

In addition to producing the print version of the evidence map, we also used the data from our evidence mapping process to develop an online, interactive map. This map is running on the 3ie evidence gap map platform developed by the International Initiative for Impact Evaluation, 3ie.

### Narrative Synthesis

The narrative synthesis expands upon the visual evidence map to provide more details from the included systematic reviews and additional synthesis from the mapping process. These include descriptions of the findings from systematic reviews, as well as a discussion of gaps and potential areas of future work.

## Peer Review

A draft version of the report was reviewed by technical experts and clinical leadership. Reviewer comments and our response are documented in Appendix E.