# APPENDIX E Peer Review Comments and Responses

## General Comments and Responses

Comment | Response
“Art Therapy" implies a single discipline, i.e. visual arts therapy. | We have updated our use of this term, as well as other related terminology, throughout the report now that we have a better understanding of their appropriate use.
The introduction (beginning line 16) misstates the definitions of creative arts therapies, expressive arts therapies, and arts in health as provided in the NOAH white paper Arts, Health and Well-being in America (pg 7) by inaccurately condensing the content and removing “creative arts therapies” from the definition. The actual definition provided in the report is “Creative Arts Therapies (CATs) include the distinct regulated health professions of art therapy, dance/movement, therapy, drama therapy, music therapy, poetry therapy, and psychodrama therapy.” | We updated quote per the suggestion to reflect the original intent of the NOAH report, which we had misread.
At line 22, the definition of Expressive Arts Therapy becomes muddled from excessive reduction of the definition provided in the White Paper (pg 7). | We have removed this description entirely as it is outside the scope of the current report.
Line 24 the definition of “arts in health” is not clear as written. Throughout this paragraph art therapy is used interchangeably with creative arts therapies, creating confusion. When referring to multiple arts disciplines, Creative Arts Therapies should be used. In a single discipline, Art Therapy, Music Therapy, Dance/Movement Therapy, etc is correct. | We have updated our use of this term, as well as other related terminology, throughout the report now that we have a better understanding of their appropriate use.
I do not the think the objectives are clearly defined. On Page 2 lines 9-14 of the Introduction, the aim is stated; however, it may be overlooked. Perhaps calling it out under a sub-heading “Intent” or Objective” may help. Note VA prefers the term ‘well-being’ over the term ‘wellness’. The Objectives may also include implications for further research as I note in utilization comment that follows later. The scope and methods are well-defined. | We have added an “Objective” heading and replaced wellbeing with well-being throughout.
Abbreviations Table (Definitions/Terminology) – Missing terms | This table now includes all abbreviations used in the report.
There is missing literature on varying subtopics such as Traumatic Brain Injury; Post Traumatic Stress Disorder and music therapy interventions. | All suggested literature from peer reviewers and searches has been incorporated. We hope this ameliorates this issue and encourage suggestions of specific literature to aid in identifying and rectifying gaps.
Research questions for the evidence review were not all explicitly stated for high priority topics that are pertinent to Veterans and active service members such as evidence mapping on suicide prevention; depression; post-traumatic stress disorder; traumatic brain injuries; pain; opioid/substance abuse; sleep; trauma or complex trauma as examples. | We now address these high-priority topics in the results and concluding sections of our report.
Yes - There are a number of articles that I was able to pull up in a quick search on some of the therapy types that the authors noted only had systematic reviews. I would think that most systematic reviews are conducted on studies that would have met the authors inclusion criteria. If a systematic review finds that there are (for example) 27 articles included, the authors should have looked over these 27 articles to identify ones that might meet the current study inclusion criteria. I think it is inaccurate to say that there are only systematic reviews available for some of the treatment modalities. I’m not sure that this is a bias, but I do think that it biases the results and conclusions drawn about where there is the most evidence. | Extracting included references from all the systematic reviews we incorporated into our evidence map would dramatically increase the work and scope of this project, something we were not able to do. Typically, evidence maps do not take this step, and many do not include literature outside of systematic reviews at all.^6^
The document includes consideration of wellness-based art therapy. As an approach to health and well-being, it is common for CATs to employ wellness-based concepts (including concepts from Positive Psychology) among populations presenting with a wide range of acuity. Wellness, as an approach across CATs, is common for prevention in healthy individuals or individuals (including veterans) transitioning in recovery from illness or injury back to the community. In thinking about the VHA’s “whole health” approach to veteran care, the distinction of health and healthy in the context of wellness-based and integrative health philosophy brings into question the fidelity of processes to filter and screen studies. What is considered healthy and would a functioning veteran or service member, for example with a hidden injury such as an acute stress reaction, be considered healthy and possibly excluded from the search herein? Exclusion of studies in this review among community-based healthy populations (p. 3, line 41), which may include veterans, raises a concern that the defined population lacks adequate specificity to focus the search objectively and avoid bias. | The original scope of the review included a population of interest of adults with any medical condition. Therefore healthy individuals, which could include veterans, who are without a diagnosed condition undergoing treatment would be excluded from the review.
Yes - Berberian, M., Walker, M. S., & Kaimal, G. (2018). “Master My Demons:” Art therapy montage painting by active-duty military service members with traumatic brain injury and post-traumatic stress. Medical Humanities. Advance online publication. doi:10.1136/medhum-2018-011493 https://www.ncbi.nlm.nih.gov/pubmed/30077986; Kaimal, G., Jones, J. P., Dieterich-Hartwell, R., Acharya, B., & Wang, X. (in press). Evaluation of long- and short-term art therapy interventions in an integrative care setting for military service members with post-traumatic stress and traumatic brain injury. Arts in Psychotherapy. Doi: 10.1016/j.aip.2018.10.003 https://www.sciencedirect.com/science/article/pii/S0197455618301321; Kaimal G., Walker, M. S., Herres J., French, L. M., & DeGraba, T. J. (2018). Observational study of associations between visual imagery and measures of depression, anxiety and post-traumatic stress among active-duty military service members with traumatic brain injury at the Walter Reed National Military Medical Center. BMJ Open, 8, e021448. doi:10.1136/bmjopen-2017-021448 (Impact factor = 2.4) https://bmjopen.bmj.com/content/8/6/e021448; Bradt, J., Biondo, J., & Vaudreuil, R. (in press). Songs created by military service members in music therapy: A Retrospective Analysis. The Arts in Psychotherapy: An International Journal. | We had not identified these in our searches, likely because they have been published so recently or are still in press. We now include the Kaimal, Jones, et al. reference in our evidence map. The study by Bradt and colleagues is of music therapy, which is no longer within the scope of our current mapping project. The others are included in our flow but were excluded because of their descriptive qualitative methodology.
My one issue is that although this is a good scoping effort at the state of the literature to potentially guide future research, I thought we were hoping for more specific information to guide clinicians in how and where to use the various therapies in this domain. Maybe the literature is not mature enough to provide that-but I fear that clinicians will not find this document so useful…. | Given the broad scope of an evidence map, the aim is to better understand the areas where work has been done and where gaps may be. Evidence maps are not intended to answer questions of effectiveness or speak to specific clinical guidance, which would be the purview of a product like a systematic review.
Using the term “Art Therapy” to refer to the overall group of creative arts therapies is very confusing because visual art therapy is commonly referred to as Art Therapy.; I strongly suggest that the more correct term “Creative Arts Therapies” be used in the title and throughout the document. The NOAH definition is a secondary source. The primary source is the National Coalition of Creative Arts Therapies Association (https://www.nccata.org):; Creative Arts Therapists are human service professionals who use arts modalities and creative processes for the purpose of ameliorating disability and illness and optimizing health and wellness. Treatment outcomes include, for example, improving communication and expression, and increasing physical, emotional, cognitive and/or social functioning. There are more than 15,000 Creative Arts Therapists practicing in the United States and around the world. Creative Arts Therapy organizations have been active in this country for over 50 years. The Coalition includes Art therapy, Dance/Movement therapy, Drama therapy, Music therapy, Poetry therapy, and Psychodrama. | We have updated our use of this term, as well as other related terminology, throughout the report now that we have a better understanding of their appropriate use.; We have incorporated a citation for NCCATA
Page 7 - link to interactive evidence map - on this page there are no titles at the top of the chart to define what population is in that particular column (it says “outcome” at the top??); I do like the ability to “hover” over the circle. | This is a constraint of the hosting platform, we are working to fix this.
Page 8 - figure 2. Evidence Map. I can’t figure out how to read this? What does 1A, 1D, !G2, 1G1 etc. mean? Where is the key for this? Would be nice if there was a little more space between the horizontal lines. | We have added more description for this, both in the text, in the figure footnote, and in the appendix.
Strengths: I like the use of visual representations of the availability of evidence for different types of art therapies. I think it is useful to see in this way. One thing to consider is that if anyone prints the article out, the bubbles all look the same color. I wonder if using a pattern and color could help differentiate the two and help improve interpretability regardless of how you view the data. | The figure is a screenshot of an interactive evidence map directly taken from the online platform. The color bubbles are part of the developer’s design, and we are unable to modify it.
The meaning of what is reported: I have been thinking about the meaning of the results, or rather how to interpret the results presented. I think the biggest challenge in my reading and understanding of what to do with the fields that only have systematic reviews mentioned. I assume that in most cases, if a systematic review has been conducted, there are likely some studies that would be included in the current one. So is it fair to say, for example, that visual art therapy has the most references? What if we looked at the systematic reviews under dance/movement therapy and found 100 articles based on impact evaluations or RCTs? It seems that there would be something wrong with the search terms rather than a lack of evidence. I understand that there may be restrictions on the scope of this review, but I think it is really hard to know what to do with the results as presented as they raise questions about what we are missing when only systematic reviews are mentioned. | Extracting included references from all the systematic reviews we incorporated into our evidence map would increase the work and scope of this project, something we were not able to do. Typically, evidence maps do not take this step, and many do not include literature outside of systematic reviews at all..^6^ Given the broad scope of an evidence map, the aim is to better understand the areas where work has been done and where gaps may be.
Some examples of missing information is already noted in the structured fields. Specific examples include for 3A2 – Systematic Reviews of Visual Art Therapy for Mood Disorders. Weiskittle and Gramling’s review of literature on the use of visual art modalities with the bereaved identifies 27 studies that have been conducted and reported on with some clinical outcomes. I pulled up this review just to see if there were any articles mentioned in the review that might meet the criteria for inclusion in the current review. It looks like there might be 5-6 articles with quantitative outcomes. I did not then go and pull those articles, but I wonder if this was done. It seems like there may be articles that have been missed. Similarly, there seems to be more literature out there for art therapy for people with schizophrenia than reported in this article. A review by Angelica Attard and Michael Larkin in Lancet Psychiatry (2016, volume 3, issue 11) found “18 high quality qualitative articles” focusing on the use of art therapy for people with schizophrenia and psychosis. For dance therapy, the systematic review conducted by Bonnie Meekums, Vicky Karkou and E Andrea Nelson (from Cochrane Systematic Review database (2015) is not mentioned. This article identifies three RCTs focusing on the use of dance movement therapy for depression, none of which are mentioned in this article either. | Extracting included references from all the systematic reviews we incorporated into our evidence map would dramatically increase the work and scope of this project, something we were not able to do. Typically, evidence maps do not take this step, and many do not include literature outside of systematic reviews at all..^2^; The qualitative articles described in the second review this reviewer identified would be out of scope as well, given that systematic reviews, RCTs, and impact evaluations with quantitative data on health outcomes were the only types of literature included.; Finally, we no longer include dance movement therapy in this map, so this final review and the related studies would also be out of the new scope.
There is very little mention of any outcomes in the presentation of results from the review. I think it would be interesting to say something about the outcomes that are included in art therapy interventions. I know that there are a number of different conditions for which art therapy is used as an intervention. But generally speaking, did you find that the outcomes were related to symptom management or improvement, experience of illness, mental health related conditions, such as depression or anxiety, etc.? This may be outside of the scope of this review, but I think it would contribute to one of the objectives of the paper, which is to inform our understanding of the volume, nature and characteristics of the research. | Speaking to the effectiveness of a treatment is typically outside the scope of an evidence map, and that is the case for this evidence map. By nature of the research we mean what quality or study design has been used to evaluate art therapy, rather than descriptions of the findings described by that research.
Page 3: Search Strategy – the language used in the first sentence is a little confusing. What do you mean you conducted broad searches from database inception? On page 4 you mentioned studies published since 1980. I think the former means since the database became available for use. It’s just a flag that I initially read these as conflicting time periods. | While our searches did pull references from much earlier than the 1980 time point, we did not include these references in our map. They are included in our literature flow though, as exclusions by date. This allows readers to see how many references were excluded for this reason.
Pages 3 Population – I don’t think of “any medical condition” as a population. I would recommend humanizing this more. Perhaps something like – “individuals diagnosed with any medical condition.” | This change has been made.
Pages 3 and 4: Inclusion – It is a little unclear who included in the study. One consideration is that the population of patients seems to be any with a diagnosed medical condition. But on page 4 - Timing - you mention mental health diagnoses. I think this is in reference to the kinds of impact outcomes you are looking for in articles included in the study, but there are some conceptual leaps that I would recommend the authors address. The section above – Outcomes – indicates you were looking for any health outcomes. In Timing it looks like it is just mental health outcomes. I think the seeming lack of alignment between Population, Outcomes and Timing makes it initially hard to track. | We have clarified population, outcomes, and timing.
Page 5: Study Design – the first sentence is missing an object. | This change has been made
Page 10: Systematic Review Findings – The first sentence is a little hard to follow. I would suggest rewording. | This has been reworded.
Page 11: I would recommend saying something more about what you found through the review. The authors most highlight the limitations of the review. This is important. But there is actually very little included about research gaps and future research. This seems like a missed opportunity. | More discussion was added here.
Page ii makes reference to the study questions. It is suggested that the study questions be explicitly stated in the report and included in Appendix A. | We have revised the sentence for clarity.
Page 2, line 21 of the document the authors state, “Therapists within these disciplines are board-certified”. It is more precise to state therapists across these professions are credentialed in accordance with national and state regulations and standards. | We have made this change.
Page 3, line 41: The sentence of exclusion is ambiguous as to intent: “…or allied health professionals, were excluded”. It is not clear whether interventions such as those employed in acute care or rehabilitation as part of individual and/or co-treatment with allied health professions are excluded in this review. For example, would a neurologic music therapy (NMT) intervention such as Rhythmic Auditory Stimulation (RAS) as part of a treatment plan with a physical therapist cotreating with a Board Certified Music Therapist with advanced training in NMT be excluded? | We have removed this example to avoid confusion, we were referring to the participants in the therapy, not who was facilitating/conducting the therapy.
Page 3, line 46: It is more precise to use the phrase “treatment modalities” since within each CAT, multiple treatment options exist for a given condition. Referring to the application of one or more CATs as “combined modalities” is confusing to clinicians since each CAT makes use of multiple interventions and approaches. Just as family nurse practitioners employ a variety of interventions, treatments, and procedures, so do music therapists, art therapists, etc. This distinction is a subtly of language use but important since CATs are not a singular, standard intervention using one theoretical framework or approach. | We have made this change.
Page 4, line 49 (and subsequent citations): “Visual art therapy” is not a term of art in standard use. Art therapy would be the preferred term referring to the profession for credentialed art therapists. | We have updated our use of this term, as well as other related terminology, throughout the report now that we have a better understanding of their appropriate use.
In addition, the summary of the systematic review findings and the narrative description of the map are largely unhelpful when it comes to understanding the respective rigor and quality of the studies mentioned therein. There is only the scantest of discussions about relative strength and weaknesses of the different studies, for each form of creative arts therapy, and how they might be improved. What are the takeaways for future researchers, in terms of designing and planning studies? Terms such as “low methodological quality” and vague formulations such as “high quality research was cited as a future need” are nowhere near helpful. | We did not appraise the quality of individual studies ourselves, as this is out of scope for our project. The findings related to study quality were from systematic reviews, and the review authors often did not supply additional details for us to report. In the summary of systematic review findings, we have provided one of the more detailed descriptions.

## Comments on Scope

Given the numerous comments about scope, we have created a second table specifically pertaining to these peer review comments. They are organized by peer reviewer. While individual reviewers provided nuance and highlighted various specific issues, there was broad agreement that a scope attempting to capture all creative Arts Therapies was too ambitious, given the constraints of time and other resources. The original scope of this project at its inception was limited to Art Therapy, and we revised the report to focus on this original scope. We agree that our attempts to stretch beyond our original scope created many of the issues described by peer reviewers below.

Comment
No - Relevance and scope of review: Given the long history of creative arts therapies with service members, veterans, and their family members, this is an important topic. Music therapy, in particular, traces its origins as a profession in service to veterans (Clair, Else, Tan, 2018) which forms an important historical context to the profession.; The title, “Evidence Map of Art Therapy” is not clear. Was the scope of the evidence synthesis review intended to focus only on art therapy interventions or broader to all creative arts therapies (CATs), including music therapy, dance movement therapy, etc.? The terminology and the title do not accurately reflect the very large scope of the review as presented. The “arts” and “art therapy” are distinct and different terms.; The scope of the review and evidence map includes all CATs and appears highly ambitious. It is suggested that the search strategy may be more effective – if/when revisited - using an alternate search plan, expanded terms, and undertaken in phases or stages. Perhaps a search by individual CAT practice area and guided - or narrowed - by specific questions would be more effective/useful. This may prove to be valuable for clinical decision making, future research, and practice policy.; Creative arts therapies include and refer to distinct professions, each utilizing multiple possible evidence-informed interventions in practice. The term art therapy or music therapy is the term applied to the profession as a whole and it is not specific to a particular theoretical framework or model that underpins an intervention or protocol. Appendix B refers to the profession (art therapy, music therapy) as an intervention which is nonspecific and technically imprecise. (For a related discussion on interventions in music therapy see www.sciencedirect.com/science/article/pii/S096522991730938X) Music therapy, in particular, consists of areas of subspecialty given its scope of practice spans a broad range of populations, conditions, and settings. I would, therefore, suggest citing the definition of each profession directly from the respective professional associations if the scope of the review includes research across all creative arts therapies and not just art therapy. Explicit statement of the research review question(s) of interest would be useful for the reader to understand the scope.; While the overall approach to the review appears sound, there is the possible bias due to overlooked literature and scope. The draft evidence map document is clearly a good fit with emerging definitions regarding the aims and purposes of evidence synthesis reviews and evidence synthesis mapping (Miake-Lye, Hempel, Shanman, & Shekelle, 2016). It is, however, a bit unusual to prepare an evidence map on a broad topic including multiple creative arts therapies and absent specific attention to the intersection of a) conditions most commonly affecting veteran (and adult) populations and b) presenting conditions most commonly seen by CATs in practice. A focused set of questions may permit a more sensitive and specific evidence map (or evidence map series).; Search strategy: It appears many peer reviewed studies were missed due to a search strategy that overlooked search terms for peer reviewed studies specific to the various creative arts therapy. The search strategy noted in Appendix A appears to assume the term [art therapy] encompasses CAT studies in addition to art therapy. For example, “music therapy” is a specific term in the NLM MeSH (https://www.ncbi.nlm.nih.gov/mesh/) and subcategories do not include art therapy. A PubMed search using MeSH term [music therapy] and publication type [clinical trial] yielded 737 hits and 630 hits if publication type was further refined to RCTs or 186 hits if publication type was limited to comparative studies.; Cochrane reviews specifically in music therapy (and this reviewer’s specific area of practice expertise) appear to be overlooked from the search. Topics include, but are not limited to, acquired brain injury, outcomes with cancer patients, schizophrenia, depression, and dementia. Similarly, SRs in the Journal of Music Therapy on topics such as pain are well cited and indexed with the NLM/PubMed but were not captured in the search strategy.; Page 4, line 16: There is a limited body of work in meta-syntheses of qualitative studies in music therapy. Data generated from rigorous qualitative research methods and combined on a topic may represent an missed opportunity in understanding the gaps in research and knowledge. Many of these questions arise and build upon the conclusions found in a meta-synthesis, inform future trials, and often touch on lines of inquiry and question types not found in RCTs seeking evidence of efficacy or effectiveness (pragmatic trials), but important to patient care, treatment, practice policy, and future research (e.g. Meadows & Wimpenny, 2017; Medcalf & McFerran, 2016).
The title is misleading. “Art Therapy” implies a single discipline, i.e. visual arts therapy. This report provides evidence in multiple creative arts therapies disciplines. A truer title would be Evidence Map of Creative Arts Therapies - Visual Art, Music, Dance/Movement Therapy. The introduction (beginning line 16) misstates the definitions of creative arts therapies, expressive arts therapies, and arts in health as provided in the NOAH white paper Arts, Health and Well-being in America (pg 7) by inaccurately condensing the content and removing “creative arts therapies” from the definition. The actual definition provided in the report is “Creative Arts Therapies (CATs) include the distinct regulated health professions of art therapy, dance/movement, therapy, drama therapy, music therapy, poetry therapy, and psychodrama therapy.” At line 22, the definition of Expressive Arts Therapy becomes muddled from excessive reduction of the definition provided in the White Paper (pg 7). Line 24 the definition of “arts in health” is not clear as written. Throughout this paragraph art therapy is used interchangeably with creative arts therapies, creating confusion. When referring to multiple arts disciplines, Creative Arts Therapies should be used. In a single discipline, Art Therapy, Music Therapy, Dance/Movement Therapy, etc is correct. This needs a thorough copy edit to correct these unfortunate mistakes to lend clarity to what is being examined here.; Yes - It’s not a bias necessarily, but in numerous places the report continues to incorrectly use Art Therapy when referring to more than one discipline including the description of the Evidence Map (line 48). Though referring to “Art Therapy Modality” in reality the evidence is showing five distinct Creative Arts Therapies modalities, including visual art therapy, dance/movement therapy, drama/psychodrama therapy, music therapy and poetry therapy. Taken together these are defined as the Creative Arts Therapies.; I am concerned that the failure to be precise in the terminology may have negatively impacted the Search Strategy, and skewed the study selections for the interventions. Line 46 again incorrectly quotes the NOAH white paper as including the six “distinct regulated health professions of art therapy” disciplines, when these are clearly outlined in the NOAH paper as belonging to the overarching category of creative arts therapies. By using the term ‘art therapy’ instead of creative arts therapies, it’s little wonder the report indicates a preponderance of art therapy studies. It seems the music therapy category is underrepresented given the longer length of time that music therapy has been undergoing research.; https://www.sciencedirect.com/science/article/pii/S0197455618301916; Vaudreuil, R., Avila, L., Bradt, J., & Pasquina, P. (2018). Music therapy applied to complex blast injury in an interdisciplinary model: A case report. The Journal of Disability and Rehabilitation. doi: 10.1080/09638288.2018.1462412 (Impact factor = 1.8); https://www.tandfonline.com/doi/full/10.1080/09638288.2018.1462412
Page 8 Line 13-27 “Art Therapy” - My understanding the study/evidence mapping would be on all the disciplines that make up the Creative Arts Therapies. There are four distinct and separate Clinical Professionals who are governed by their respective accreditation bodies – Art Therapy; Music Therapy; Drama Therapy and Dance/Movement Therapy. The term “Art Therapy” does not encompass professional work of the other professions i.e. Music therapy, Dance Therapy and Drama Therapy. Page 8 line 17 – professions of “art therapy” is inaccurate. Art Therapy is it’s own specific profession and does not encompass the other professional disciplines.; Page 8 line 26/27 - considered a distinct from art therapy. I believe art therapy in this context you are referring to the Creative Arts Therapies and should not be grouped into the term Art Therapy. You could reference National Coalition of Creative Arts Therapies Associations, Inc. This is made up of the professional organization for each of the distinct Therapies that make up creative arts therapy professionals i.e. Art Therapy – American Art Therapy Association; Music Therapy – American Music Therapy Association; Dance Therapy - American Dance Therapy Association; Drama Therapy - North American Drama Therapy Association.; General Comments; The scope of the intended scope – it appears the scope of project is attempting to look at literature and evidence across the four distinct professional groups of art therapy; music therapy; dance/movement therapy and drama therapy across all clinical topics. However, the literature search to appears to have only utilized primary term Art therapy which does not provide or excludes data related to the other terms/professions such as Music Therapy (MT); Dance/Movement Therapy (DMT); Art Therapy (AT), etc. The text appears to treat the term “art therapy” as a Intervention rather than the name of each of the professions. Each of the professions have unique credentials for the associated profession.; Terminology – appears the term art therapy is attempting to encompass all therapies. This is misunderstood term and not inclusive of the other creative arts therapy professionals – music therapy, drama therapy, dance/movement therapy. In addition, the term art therapy seems to represent an intervention when that actually is term used for the profession itself and not the intervention specifically.; The term art therapy within the literature search is missing a considerable amount of research from the other professions such as music therapy, dance/movement therapy and drama therapy. That is a gap in the use of the term “art therapy” to try to encompass all of the other professions. There is missing literature on varying subtopics such as Traumatic Brain Injury; Post Traumatic Stress Disorder and music therapy interventions.; Research questions for the evidence review were not all explicitly stated for high priority topics that are pertinent to Veterans and active service members such as evidence mapping on suicide prevention; depression; post-traumatic stress disorder; traumatic brain injuries; pain; opioid/substance abuse; sleep; trauma or complex trauma as examples.; It would be good to add a credentialed academic scholar for each of the professions represented (Board Certified Music Therapist; Board Certified Art Therapists; Board Certified Dance Therapist; etc. to the Technical Expert Panel (TEP) section of the study. There was peer reviewers with credential however they would have limited scope whereas if added to TEP that could help provide improved Guide topic refinement and ensure proper terminology usage is used to capture full scope of the work and literature.; In general it appears - term art therapy was misunderstood and utilized to capture full extent of the project but was missing literature that impacts the overall creative arts therapy professionals work related to the professions of art therapy, music therapy, dance/movement therapy etc.; Topics for interventions utilized by the credentialed therapist in the professions of music therapy, dance/movement therapy and drama therapy were missed which resulted in potential lost information on outcomes related to the delivery of interventions used by the professionals.; Would request to re-run literature search using alternative searching strategies to include terms that impact creative arts therapist in music therapy, dance/movement therapy etc. Execution of updating terms and also adding in a few more individuals from the professional associations would improve the result of the study and provide more meaningful data to the Program offices for decision making and strategic planning.; Yes - See above comments
Yes - The search criteria, which focuses on the term “art therapy,” has weighted the review toward the (visual) art therapy. Suggestions for improved search criteria are included in my attachment.; Yes - I am concerned that many studies focused on music therapy have been overlooked. Note, for example, Music interventions for improving psychological and physical outcomes in cancer patients by J Bradt, C Dileo, L Magill, A Teague (2016), which is included in the Cochrane Database of Systematic Reviews.
Yes - Distressingly, this report’s search criteria (and the very title of the synthesis) betray an unwitting bias toward “art therapy” (that is, visual art therapy) over music therapy, dance and/or movement therapy, drama and/or theater therapy, and expressive or creative writing therapy. For a report of this type, it is crucial to use search terms that don’t lock one into a particular arts modality. Appendix A explains that “art therapy” was indeed a pivotal search term, possibly at the expense of these other types of creative arts therapies. In short, the search terms are terrifically biased, if I read the appendix correctly.; Yes - I’m sure there are, due to the unfortunate search criteria (see above).
Yes - Perhaps not bias so much as lack of clarity in the conflation of “art therapy” and “creative arts therapies,” as well as lack of comprehensive inclusion of literature in the synthesis.; Yes - See my comments below.; It appears that the title and the terms used in the manuscript do not accurately reflect the review. The “arts” and “art therapy” are distinct and different terms. Further, it is unclear as to whether the scope of the synthesis review was intended to target art therapy interventions, or all creative arts therapies. Furthermore, some of the contents of the NOAH White Paper are misquoted. For example, please refer to my comments (related to content on page 8 of the PDF file - in ALL CAPS):; “The National Organization for Arts in Health (NOAH) identifies six “distinct regulated health professions of art therapy” (SIX DISTINCT REGULATED PROFESSIONS) which have “a definition of the profession, a legally defensible scope of practice, educational competencies, standards of practice, code of ethics, and evidence-based research.”1 These include art therapy, dance/movement therapy, drama therapy, psychodrama therapy (STRIKE “THERAPY,” PSYCHODRAMA IS KNOWN SOLELY AS PSYCHODRAMA), music therapy, and poetry therapy. Therapists within these disciplines are board certified (THEY SHOULD BE BOARD CERTIFIED, BUT THAT’S NOT ALWAYS THE CASE. SOME STOP AT NATIONAL REGISTRATION CREDENTIALS. OTHERS GO BEYOND BOARD CERTIFICATION AND OBTAIN LICENSURE SPECIFIC TO THEIR DISCIPLINE (OR OTHER, DEPENDING ON THE SITUATION IN A GIVEN STATE, SUCH AS COUNSELING LICENSURE). When these different modalities or disciplines are blended or combined by trained professionals this is referred to as expressive art therapy (THIS IS AN IMPORTANT DISTINCTION: I HAVE EDITED THIS SENTENCE SO AS TO CLARIFY, AND AVOID MISLEADING, THAT EXPRESSIVE ARTS THERAPY IS NOT REGULATED IN THE WAY THAT THE DISTINCT CATS PROFESSIONS ARE: “CONVERSELY, WHEN THESE DIFFERENT ARTS MODALITIES ARE COMBINED BY TRAINED PROFESSIONALS, THIS IS REFERRED TO AS EXPRESSIVE ARTS THERAPY.). While arts can be used in other ways within health care and public health, these arts in health programs are not led by trained therapists, but rather artists or other types of coordinators, and are considered distinct from CLINICAL CREATIVE ARTS THERAPIES.; THE CREATIVE ARTS THERAPIES ARE used in the treatment of a variety of conditions, including schizophrenia,2 depression,3 and stroke rehabilitation.4 Given the breadth of conditions to which CREATIVE artS therapIES haVE been applied (STRIKE: “and the variety of disciplines under the umbrella of creative art therapy” - REDUNDANT), we conducted an evidence mapping …”; I would encourage the authors to carefully consult the NOAH White Paper, https://thenoah.net/wp-content/uploads/2019/01/NOAH-2017-White-Paper-Online-Edition.pdf, which includes definitions of the distinct CATs professions, as sanctioned by each profession’s national organization. On page 26 of the White Paper/PDF, Table 1, Creative Arts Therapies Professions Overview, includes an overview of the CATs professions. This information was provided by the national CATs organizations, therefore it is an accurate and trustworthy source.
Yes - Referring to the modalities as defined by Noah as “Art Therapy” is a concern to me. Practicing creative arts therapist may not being lumped into an “Art Therapy” category. Suggest replacing art therapy with ‘Creative Arts Therapy’, ‘Creative Arts Therapies’ or the plural “Arts Therapy”. Using the term, “Art Therapy” to refer to the larger spectrum of modalities may imply the authors did not fully grasp an understanding of the topic as Art Therapy in itself is a singular modality/profession.; Yes - I note that your search strategy included the key words “Art Therapy” and wondering if the individual modalities “Music therapy, Dance Therapy, etc. might have yielded more eligible studies. I am disappointed at the limited number of references that met your criteria for rigor – only 102 out of the original 1132 identified (only 10%). Is this solely an indicator of the lack of Randomized Controlled Trial, quantitative impact evaluations with health outcome data, or systematic reviews out there or the poor quality of the research in this field or could the search have been expanded?
Yes - See my comment above. I think that there are probably a number of quantitative impact or RCT studies missed in this review. One example is for dance movement therapy. Meekums et al (2015) did a Cochrane Review and identified 3 RCTs. I don’t see this included, or the articles (Jeong, 2005; Xiong, 2009; Rohrict, 2013). I wrote out some additional ones in my narrative comments.; If the articles want to be inclusive, I would recommend reviewing the systematic reviews to identify articles that the search strategy missed. Not all of the systematic reviews included articles that would be included in the current review, but I think there are a number that the authors will find.; Missing articles: I have some concerns about the search process and am not confident that the results reported reflect the literature that is out there about art therapy. I think reliance on just the terms “art therapy” (or parts thereof) may underlie some of the missing data from this review. The authors noted in the summary that using terms specific to different disciplines was outside of the scope of the review. But I think that at least adding the different types of art therapies would be helpful. I would suggest adding to the search with those additional key terms in order to be more inclusive.
There were few qualified studies from several of the NOAH defined Creative Arts Therapy professions. a search specific to each of the defined areas may add value. Music Therapy, Art Therapy, Dance Therapy, Drama Therapy, Poetry Therapy, Psychodrama.