# APPENDIX C Full-Text Screening Form

1. Study design
  a. Systematic review
  b. RCT
  c. Other impact evaluation/descriptive quantitative for health outcomes
  d. Descriptive qualitative EXCLUDE STOP FORM (including case reports)
  e. Non-systematic review/commentary/editorial with no original data EXCLUDE STOP FORM
  f. Background EXCLUDE STOP FORM (including descriptive quantitative without health outcomes data)
2. Interventions
  a. Visual art therapy
  b. Dance/movement therapy
  c. Drama/psychodrama therapy
  d. Music therapy
  e. Poetry therapy
  f. MBAT
  g. Mixture/combination
  h. Other art therapy – specify: ________________
  i. Other intervention/therapy/art as a diagnostic tool EXCLUDE STOP FORM (including activities or programs led by non-art therapists)
3. Population
  a. Alzheimer’s/dementia
  b. PTSD
  c. Substance abuse^**^
  d. TBI^**^
  e. Mood disorders (eg depression, anxiety)
  f. Cancer/palliation
  g. Schizophrenia/psychosis
  h. Other psychiatric, specify: ___________
  i. Other non-psychiatric (including rehab, stroke, etc.), specify: __________
  j. Pediatric EXCLUDE STOP FORM
  k. Healthy people EXCLUDE STOP FORM
4. For Systematic Reviews Only: Number of included impact evaluations: ________________
5. For Systematic Reviews Only: Short description of findings. Include strength of evidence and main findings.

** These 2 populations do not appear in the report because no studies were found related to them. These were categories initially suggested by team members for categorizations.