# APPENDIX A Search Strategy

## Art Therapy – Search Methodology

### Database Searched & Time Period Covered

PUBMED – from inception to 5/15/2018

### Language

English

### Search Strategy #1

"Art Therapy"[Mesh] OR art therap*

### Search Strategy #2 (Subset of Search #1 to Identify Systematic Reviews & Meta-Analyses)

"Art Therapy"[Mesh] OR art therap*

AND

systematic review* OR meta-analy* OR meta analy* OR metaanaly* OR FILTERS: Meta-Analysis; Systematic Reviews

### Search Strategy #3 (Subset of Search #1 to Identify RCTs)

"Art Therapy"[Mesh] OR art therap*

AND

randomi* OR rct* OR FILTER: Randomized Controlled Trial

=====================================================================

### Database Searched & Time Period Covered

PsycINFO – 1/1/2000- 5/15/2018

### Language

English

### Search Strategy #1

DE “Art Therapy” OR “art therapy”

### Note – The Results of this Search were not Downloaded Due to the Large Number of Results

### Search Strategy #2: Database Searched & Time Period Covered

PsycINFO – 1/1/1990 - 5/15/2018

### Language

English

### Search Strategy

DE “Art Therapy” OR “art therapy”)

AND

systematic review OR systematic reviews OR meta-analy* OR meta analy* OR metaanaly*

OR

DE “Art Therapy” OR “art therapy”

Narrow by Methodology: - meta analysis

Narrow by Methodology: - systematic review

### Search Strategy #3: Database Searched & Time Period Covered

PsycINFO – 1/1/2000 - 5/15/2018

### Language

English

### Search Strategy

DE art therapy OR “art therapy”

AND

randomi* OR rct*

OR

DE “Art Therapy” OR “art therapy”

Narrow by Methodology: - clinical trial