# Acknowledgments

This topic was developed in response to a nomination by Donna Faraone, Field Implementation Team Lead and Music Therapist/Office of Patient Centered Care and Cultural Transformation, David Otto, National Program Director/Recreation Therapy Service (10P4RR), and Ben Kligler, National Director/Coordinating Center for Integrative Health, for the purpose of supporting decisions related to the use of arts and humanities to improve Veteran health in the VHA. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In determining the scope of the report and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge 3ie for the use of their evidence gap map platform, and Roberta Shanman, MLS, for her contribution to this project.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Donna Faraone, MPA, CPHQ
  Field Implementation Team Lead/Music Therapist
  Office of Patient Centered Care and Cultural Transformation (10NE)
- David Otto, MME, MT-BC
  National Program Director, Recreation Therapy Service (10P4RR)
  Rehabilitation and Prosthetic Services (10P4R)
- Ben Kligler, MD, MPH
  National Director, Coordinating Center for Integrative Health
  Office of Patient Centered Care and Cultural Transformation (10NE)

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Judy A. Rollins
  Author, Artist, Researcher – Americans for the Arts
  Walter Reed National Military Medical Center
- Patricia M. Shaffer
  Deputy Director of Research & Analysis
  National Endowment for the Arts
- Cyndi Wilson
  Field Implementation Team Consultant and Arts and Humanities Community Engagement
  Coordinator, Office of Patient Centered Care and Cultural Transformation
  VA Western New York Healthcare System
- Teresa Bush-Zurn
  Field Implementation Team Consultant
  Office of Patient Centered Care and Cultural Transformation

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.