# Abbreviations Table

CAT: Creative arts therapies
CCT: Chinese calligraphy therapy
CPI: Creative psychological interventions
DMT: Dance/movement therapy
DSM: Diagnostic and Statistical Manual of Mental Disorders
ESP: Evidence Synthesis Program
MBAT: Mindfulness-based art therapy
NOAH: National Organization for Arts in Health
PTSD: Posttraumatic stress disorder
QoL: Quality of life
RCT: Randomized control trials
TBI: Traumatic brain injury
TEP: Technical expert panel
3ie: International Initiative for Impact Evaluation