# References

1 Berkman ND, Lohr KN, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. 2013 Nov 18. In: Methods Guide for Effectiveness and Comparative Effectiveness Reviews [Internet]. Rockville (MD): Agency for Healthcare Research and Quality (US); 2008. Available from: https://www.ncbi.nlm.nih.gov/books/NBK174881/.
2 Cooke B, Ernst E. Aromatherapy: a systematic review. Br J Gen Pract. 2000;50(455):493–496.10962794
3 Aziz ZAA, Ahmad A, Setapar SHM, . Essential Oils: Extraction Techniques, Pharmaceutical And Therapeutic Potential - A Review. Current drug metabolism. 2018;19(13):1100–1110.30039757
4 Gonzalez-Mas MC, Rambla JL, Lopez-Gresa MP, Blazquez MA, Granell A. Volatile Compounds in Citrus Essential Oils: A Comprehensive Review. Frontiers in plant science. 2019;10:12.30804951
5 Chida Y, Steptoe A, Hirakawa N, Sudo N, Kubo C. The effects of psychological intervention on atopic dermatitis. A systematic review and meta-analysis. Int Arch Allergy Immunol. 2007;144(1):1–9.17449959
6 Snow LA, Hovanec L, Brandt J. A controlled trial of aromatherapy for agitation in nursing home patients with dementia. J Altern Complement Med. 2004;10(3):431–437.15253846
7 Carson CF, Hammer KA, Riley TV. Melaleuca alternifolia (Tea Tree) oil: a review of antimicrobial and other medicinal properties. Clin Microbiol Rev. 2006;19(1):50–62.16418522
8 Tariq S, Wani S, Rasool W, . A comprehensive review of the antibacterial, antifungal and antiviral potential of essential oils and their chemical constituents against drug-resistant microbial pathogens. Microb Pathog. 2019;134:103580.31195112
9 Joswiak D, Kinney ME, Johnson JR, . Development of a Health System-Based Nurse-Delivered Aromatherapy Program. J Nurs Adm. 2016;46(4):221–225.27011157
10 Knutson L, Johnson PJ, Sidebottom A, Fyfe-Johnson A. Development of a hospital-based integrative healthcare program. J Nurs Adm. 2013;43(2):101–107.23343726
11 Hardy M, Kirk-Smith MD, Stretch DD. Replacement of drug treatment for insomnia by ambient odour. Lancet. 1995;346(8976):701.
12 Miake-Lye IM, Hempel S, Shanman R, Shekelle PG. What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Systematic reviews. 2016;5:28.26864942
13 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–46.27005575
14 Wallace BC, Small K, Brodley CE, Lau J, Trikalinos TA. Deploying an interactive machine learning system in an evidence-based practice center: abstrackr. Proceedings of the 2nd ACM SIGHIT International Health Informatics Symposium (IHI). 2012:819–824.
15 Shea BJ, Grimshaw JM, Wells GA, . Development of AMSTAR: a measurement tool to assess the methodological quality of systematic reviews. BMC Med Res Methodol. 2007;7:10.17302989
16 Fung JK, Tsang HW, Chung RC. A systematic review of the use of aromatherapy in treatment of behavioral problems in dementia. Geriatr Gerontol Int. 2012;12(3):372–382.22433025
17 Biddiss E, Knibbe TJ, McPherson A. The effectiveness of interventions aimed at reducing anxiety in health care waiting spaces: a systematic review of randomized and nonrandomized trials. Anesth Analg. 2014;119(2):433–448.24942321
18 Hsu CH, Chi CC, Chen PS, Wang SH, Tung TH, Wu SC. The effects of aromatherapy massage on improvement of anxiety among patients receiving palliative care: A systematic review of randomized controlled trials. Medicine (Baltimore). 2019;98(9):e14720.30817616
19 Perry R, Terry R, Watson LK, Ernst E. Is lavender an anxiolytic drug? A systematic review of randomised clinical trials. Phytomedicine. 2012;19(8–9):825–835.22464012
20 Choi J, Lee JA, Alimoradi Z, Lee MS. Aromatherapy for the relief of symptoms in burn patients: A systematic review of randomized controlled trials. Burns. 2018;44(6):1395–1402.29169701
21 Wilkinson S, Barnes K, Storey L. Massage for symptom relief in patients with cancer: systematic review. J Adv Nurs. 2008;63(5):430–439.18727744
22 Sanchez-Vidana DI, Ngai SP, He W, Chow JK, Lau BW, Tsang HW. The Effectiveness of Aromatherapy for Depressive Symptoms: A Systematic Review. J Evid Based Complementary Altern Med. 2017;2017:1–21.
23 Lee MS, Lee HW, Khalil M, Lim HS, Lim HJ. Aromatherapy for Managing Pain in Primary Dysmenorrhea: A Systematic Review of Randomized Placebo-Controlled Trials. J Clin Med. 2018;7(11):10.
24 Bouya S, Ahmadidarehsima S, Badakhsh M, Balouchi A, Koochakzai M. Effect of aromatherapy interventions on hemodialysis complications: A systematic review. Complement Ther Clin Pract. 2018;32:130–138.30057040
25 Hur MH, Lee MS, Kim C, Ernst E. Aromatherapy for treatment of hypertension: a systematic review. J Eval Clin Pract. 2012;18(1):37–41.20695948
26 Chen SF, Wang CH, Chan PT, . Labor pain control by aromatherapy: A meta-analysis of randomized controlled trials. Women and Birth : Journal of the Australian College of Midwives. 2018;18:18.
27 Hines S, Steels E, Chang A, Gibbons K. Aromatherapy for treatment of postoperative nausea and vomiting. The Cochrane Database of Systematic Reviews. 2018;3:CD007598.29523018
28 Matthews A, Haas DM, O’Mathuna DP, Dowswell T. Interventions for nausea and vomiting in early pregnancy. The cochrane Database of Systematic Reviews. 2015(9):CD007575.26348534
29 Koog YH, Jin SS, Yoon K, Min BI. Interventions for hemiplegic shoulder pain: systematic review of randomised controlled trials. Disabil Rehabil. 2010;32(4):282–291.20055567
30 Dimitriou V, Mavridou P, Manataki A, Damigos D. The Use of Aromatherapy for Postoperative Pain Management: A Systematic Review of Randomized Controlled Trials. J Perianesth Nurs. 2017;32(6):530–541.29157760
31 Lederer AK, Schmucker C, Kousoulas L, Fichtner-Feigl S, Huber R. Naturopathic Treatment and Complementary Medicine in Surgical Practice. Dtsch Arztebl Int. 2018;115(49):815–821.30678751
32 Babakhanian M, Ghazanfarpour M, Kargarfard L, . Effect of Aromatherapy on the Treatment of Psychological Symptoms in Postmenopausal and Elderly Women: A Systematic Review and Meta-analysis. J Menopausal Med. 2018;24(2):127–132.30202763
33 Khadivzadeh T, Najafi MN, Ghazanfarpour M, Irani M, Dizavandi FR, Shariati K. Aromatherapy for Sexual Problems in Menopausal Women: A Systematic Review and Meta-analysis. J Menopausal Med. 2018;24(1):56–61.29765928
34 Hu RF, Jiang XY, Chen J, . Non-pharmacological interventions for sleep promotion in the intensive care unit. The Cochrane Database of Systematic Reviews. 2015(10):CD008808.26439374
35 Lillehei AS, Halcon LL. A systematic review of the effect of inhaled essential oils on sleep. J Altern Complement Med. 2014;20(6):441–451.24720812
36 Hur MH, Song JA, Lee J, Lee MS. Aromatherapy for stress reduction in healthy adults: a systematic review and meta-analysis of randomized clinical trials. Maturitas. 2014;79(4):362–369.25234160
37 Li H, Zhao M, Shi Y, . The effectiveness of aromatherapy and massage on stress management in nurses: A systematic review. J Clin Nurs. 2019;28(3–4):372–385.29964364
38 Cao H, Yang G, Wang Y, . Complementary therapies for acne vulgaris. The Cochrane Database of Systematic Reviews. 2015;1:CD009436.25597924
39 Costa MF, Durco AO, Rabelo TK, Barreto RSS, Guimaraes AG. Effects of Carvacrol, Thymol and essential oils containing such monoterpenes on wound healing: a systematic review. J Pharm Pharmacol. 2019;71(2):141–155.30537169
40 Martin KW, Ernst E. Herbal medicines for treatment of fungal infections: a systematic review of controlled clinical trials. Mycoses. 2004;47(3–4):87–92.15078424
41 Ueki S, Matsunaka E, Swa T, Ohashi K, Makimoto K. Effectiveness of inhalation of aromatherapy in reducing anxiety in patients before colonoscopy: a systematic review protocol. JBI Database Of Systematic Reviews And Implementation Reports. 2015;13(9):40–50.26470659
42 Langley T, Geiger W, Gartlehner G. Aromatherapy for pain relief and psychological problems. Systematic review (Structured abstract). Health Technology Assessment Database. 2016(4).
43 Posadzki P, Alotaibi A, Ernst E. Adverse effects of aromatherapy: a systematic review of case reports and case series. Int J Risk Saf Med. 2012;24(3):147–161.22936057
44 Su HJ, Chao CJ, Chang HJ, Wu PC. The effects of evaporating essential oils on indoor air quality. Atmos Environ. 2007;41(6):1230–1236.
45 Cook A, Burkhardt A. Aromatherapy for Self-Care and Wellness. Vol 102004.
46 Berkman N, Lohr K, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. Rockville, MD: Agency for Healthcare Research and Quality; Methods Guide for Comparative Effectiveness Reviews (AHRQ Publication No. 13(14)-EHC130-EF);2013.