# Acknowledgments

This topic was developed in response to a nomination by the Office of Patient Centered Care and Cultural Transformation (OPCC&CT) to guide the use of aromatherapy and essential oils in the VHA. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Robin Paynter, MLIS, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Ben Kligler, MD, MPH
  National Director, Integrative Health Coordinating Center
  VA Central Office, Washington, DC
- Peter A. Glassman, MBBS, MSc
  Chair, Medical Advisory Panel, Pharmacy Benefits Management Services
  VA Greater Los Angeles Healthcare System

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Leila Kozak, PhD
  Whole Health National Champion, OPCC&CT – IHCC, VA Puget Sound HCS
  Director, Integrative Palliative Care Institute (IPCI)
- Angie Lillehei, PhD MPH RN
  Chief Integrator, Minnesota Personalized Medicine
  Owner and Principal, Noctilessence LLC
- Linda L. Halcon, PhD, MPH, RN
  Associate Professor Emerita, University of Minnesota School of Nursing
- Margo A. Halm, RN, PhD, ACNS-BC
  Associate Chief Nurse Executive, Nursing Research/ EBP & Magnet Director, Portland VAHCS

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.